# APPENDIX I INTERVENTION RESOURCE NEEDS

Author, Year, PMID | Staffing Needs and Mix | Environment | Programming | Space Requirements | Equipment Needs | Documentation Needs | Time to Perform Checks on Patients | Time to Perform Documentation | Changes in Service Provision
Hospital/Unit Restructuring
Hochstrasser 2018 29331599 | NR | NR | NR | NR | NR | NR | NR | NR | NR
Hunter 1993 8444440 | Housing program staffed by mental health workers; intensive unit staffed by nurses. Multidisciplinary team responsible for all day hospital and intensive care patients regardless of which unit they are located at any given time | NR | Group based recreation program with activities in a community setting intended to raise residents’ level of functioning and promote their return to community living | NR | NR | Upon admission to acute day hospital patients are evaluated to determine intensive care unit or residential program placement | NR | NR | Patients transferred to different units maintained the same care team throughout their stay; Intensive inpatient unit restructured around group-based treatment
Rohe 2017 26820456 | NR | NR | NR | NR | NR | NR | NR | NR | NR
Jenkins 2014 No PMID | NR | NR | NR | Ensuite facilities for bedrooms, greater privacy as each bedroom was a single, separate Section 136 facilities (areas to assess patients detained by the police), gender specific areas, visiting area, designated activities room and a seclusion area conforming to Department of Health guidelines. | NR | NR | NR | NR | NR
Staff Education/Training
Bowers 2008 18844799 | Two City nurses were appointed for the project who were clinical experts in acute inpatient care with long experience in practice development | NR | A structure of rules and routines for ward life was implemented | NR | NR | NR | NR | NR | NR
Forster 1999 10565060 | Management of Assaultive Behavior team consisted of a multidisciplinery group who met biweekly; “charismatic leader” headed staff training program | NR | NR | NR | NR | NR | NR | NR | NR
Haefner 2021 32749904 | Multidisciplinary team of registered nurses, psychiatric pharmacy technicians, psychiatric nurse practitioners, social workers, occupational therapists and activity therapists | NR | NR | NR | NR | NR | NR | NR | NR
Sensory Modulation
Lloyd 2013 No PMID | NR | NR | NR | Psychiatric intensive care room converted into sensory modulation room | $5,000 of sensory modulation equipment including bean bag chairs, musical instruments, therapy balls and aromatherapy | Screening form to determine which sensory modulation format would benefit the patient | NR | NR | NR
Cummings 2010 20349887 | Multiple staff members including nursing staff, executive staff and managers, representatives from maintenance, engineering, staff development, and rehabilitation departments involved in brainstorming and setting up the comfort room over a 2 year period | NR | NR | Comfort room to promote a healthy, therapeutic, supportive, and safe environment; locked from the outside allowing patients to leave when they no longer felt distressed | Lighting with a dimmer switch, wallpaper, light blue wall paint, multisensory reclining chair, oak entertainment center with a television DVD/VCR and CD player, calming music, books, puzzles, weighted blankets, stress balls, and magazines. | After each instance of comfort room use, staff documented whether the episode was considered effective in reducing distress | NR | NR | NR
Azuela 2018 No PMID | NR | NR | NR | NR | NR | NR | NR | NR | NR
Novak 2012 23014117 | NR | Sensory room created a homely environment including scenic pictures and comfortable furnishing | NR | An existing interview room was converted into a sensory room | Comfortable furnishings and a range of sensory modulation items including weighted blanket, music, magazines, books, rocking chair, scents, and fit ball | A sensory room assessment form was developed. Consumers rated their level of distress on a 10-point scale and clinicians rated 11 common behavioral disturbances before and after room use. Age diagnosis, duration of use, whether medication was used, what items were used in the room and whether seclusion was required was also documented | NR | NR | NR
Sivak 2012 22439145 | Multidisciplinary team including financial office representative to approve costs, procurement office representative to assist with ordering, performance improvement department representative for data collection, a psychologist, activity department representative for comfort measures guidance, 2 direct-care RNs, 2 nursing supervisors, carpenter for comfort room construction, infection control nurse and safety manager | NR | NR | One room on each unit was converted into a comfort room; comfort rooms installed with drop ceilings for noise control and sky scene light panels to improve ambiance; chalkboard covered wall and mural wall voted on by clients placed in each comfort room | Recliner, rocking chair, foam chair, carpets, lap desk, television, and Blu-ray disc player in each comfort room | Comfort room use login sheet; comfort room agreement form signed by clients prior to each use; comfort room voluntary feedback form | NR | NR | NR
Smith 2013 24305908 | NR | NR | NR | Sensory room was 5 meters by 2.5 meters with light blue painted walls, laminate flooring and one window with a black out roller blind | Large floor mounted bubble tube, an optic mat, a light/image emitting projector, 2 lying bean bags, 2 sitting bean bags, a variety of cushions, an iPod dock/ iPod and drawers containing; magazines, stress relief toys, chewing gum and educational materials promoting relaxation and healthy living | NR | NR | NR | NR
Zimmermann 2020 No PMID | Human service workers and nursing staff responsible for supervising the use of serenity room | NR | NR | Serenity room to provide a safe environment for patients to self-soothe and practice alternative coping strategies | Rocking chair, oversized bean bag, curtains, inspirational quotes and chalkboard wall, built in desk area, sound machine, kinetic sand, stretch balls and strings, fidget spinners, inspirational books, liquid filled non-toxic floor tiles, Himalayan salt lamp night light, and squeeze balls | NR | NR | NR | NR
Risk Assessment
Abderhalden 2008 18700217 | Group staff meetings to discuss preventive measures for a small subgroup of high-risk patients | NR | NR | NR | NR | Structured short-term risk assessment for every new patient during the first 3 days of hospitalization and twice daily thereafter | NR | Short-term risk assessment completed within 3 days of admission and twice daily during the rest of the inpatient stay | NR
van de Sande 2011 22016437 | NR | NR | NR | NR | NR | The Crisis Monitor for early recognition of patterns associated with escalation and symptom severity change; Brøset Violence Checklist and the Kennedy–Axis V (short version) scale to identify risks of loss of control; Kennedy–Axis V (full version), Brief Psychiatric Rating Scale (BPRS), Dangerousness Scale, Social Dysfunction and Aggression Scale to evaluate mental state changes and current patient behavior | NR | 5 minutes per patient to administer daily Crisis Monitor; 15 minutes per patient to administer weekly assessment measures | NR
Blair 2017 26897657 | NR | NR | NR | NR | NR | Medical Director and the Director of Nursing examined all S/R events to determine if a formal administrative review was needed (based on severity and outcome). Review included questions on staff knowledge of the patient, the specific de-escalation intervention(s) used and the communication about the patient’s status prior to the event. | Physician review frequency increased to every 2 h from every 4 h for patients over the age of 18 | NR | NR
Clarke 2010 20712684 | Six full-time nursing staff charged with the responsibility of completing the Brøset Violence Checklists | NR | NR | NR | NR | Brøset Violence Checklist completed by general duty nursing staff for each patient assigned to him or her on each shift | NR | Brøset Violence Checklist completed during each nursing shift for the first 72 h of admission | NR
Harrington 2019 31206989 | Patients categorized as medium risk were allocated a contact nurse responsible for ensuring that regular engagements occurred; patients in the high-risk category managed in either a secure high-care area with a staff: patient ratio of 2:5 or in the open ward with 1:1 nursing. | NR | NR | Secure high-care area for high-risk patient population | NR | Risk assessment completed on admission, when mental status changed, or at a minimum of once per week to categorize patients as ‘low’, ‘medium’, or ‘high’ risk; Medium and high risk patients had risk reviews regularly throughout the day while low risk patients had risk reviews 1× per shift; Patient Safety Plan captured possible early warning signs for change in risk, activities to decrease exacerbation of risk and management strategies | Ward rounds conducted 2–3× an hour and at strategic times such as shift change and meal time; Medium risk patients required an initial comprehendsive engagement by contact nurse and subsequent reviews occurred no less frequently than 1× an hour; patients requiring 4+ engagements an hour were reviewed for change is risk status to high-risk’ patients requiring only hourly engagements were considered for change to low-risk | Risk assessments were completed on admission, at first psychiatrist consultant review, and with change in mental status; Risk review conducted 1× per shift for low-risk patients; risk reviewed conducted regularly throughout the day for medium and high-risk patients | NR
Manning 2022 36006571 | NR | NR | NR | NR | NR | Modified Agitation Severity Scale (MASS) to assess current severity of patient agitation | NR | One minute to score the Modified Agitation Severity Scale at time of admission and then twice daily per patient | NR
Trauer 2010 No PMID | Staff not involved in the MAAP event engaged in a patient debriefing; A Practice Development Nurse was appointed for the six month implementation to provide training and ongoing support and monitoring; Senior clinicians would perform informal check-ins with shift leaders and staff about MAAP initiation | NR | NR | Time-out areas away from others were required for patients to voluntarily go when experiencing distress | NR | Nursing staff initially assessed patients displaying agitated or aggressive behavior using the Fremantle Arousal Scale^35^; All assessments and interventions were recorded on specially designed forms. | Reassessments and variation in management occurred every 15 to 30 minutes | De-briefings occurred 24–48 hours after the MAAP event | NR
Comprehensive/Mixed
Bowers 2015 26166187 | Large number of research staff operated across multiple sites; completion was dependent on the support of nursing staff to engage with the trial and undertake new and additional activities | NR | NR | NR | Crate of distraction and sensory modulation tools including stress toys, mp3 players with soothing music, light displays, textured blankets, etc | NR | NR | NR | NR
Välimäki 2022 36040740 | NR | NR | NR | NR | NR | NR | Physician review frequency increased to every 2 h from every 4 h for patients over the age of 18 | NR | NR
Boumans 2014 23890418 | Active involvement of staff for program preparation | NR | NR | NR | NR | Decisions documented in a care plan and goals regularly evaluated by a coordinating nurse | NR | NR | NR
Noorthoorn 2014 No PMID | NR | NR | NR | NR | NR | During a first admission, information was gathered to compile specified signaling plans (ie, plans aimed at early detection of behavior preceding aggression) | NR | NR | NR
Blair 2015 25751828 | Managers offer themselves as resources to staff; staff expected to take initiative in creating early self-management plans; 1 staff member may remain with a more challenging patient, engaging with him or her on a consistent basis until he or she begins to stabilize; management team performed a root cause analysis on all incidents of S/R; increased staff presence on ward. | Staff eat family-style meals with patients; An increased staff presence in the milieu can take the form of sitting and chatting with patients over a cup of coffee, playing a game of cards with patients, or reading a newspaper or magazine in the day area during a downtime. | 2× daily community meetings reinforce community structure, provides stability, emphasizes safety, invites openness, enhances cohesiveness and enables patients to be heard; A special community meeting can be held, to address problems or debrief an incident; Special groups focused on active practice of relaxation or distraction techniques. | Two small side rooms are used as patient television viewing areas, so that the main day area promotes conversation and personal interactions; Rooms may be made available where patients can go for a quieter atmosphere. | Music/headphones, authorized use of computers, supervised use of guitar or karaoke equipment | Admission screening tools provide information about individual patient trauma history, triggers, history of assault or aggression, and strategies the patient finds helpful for self-calming. | NR | NR | NR
Dickens 2020 32691495 | NR | NR | NR | NR | Sensory boxes funded from project resources, sourced and constructed by the project officer | NR | NR | NR | NR
Hellerstein 2007 17890979 | Two staff members available to escort an individual patient off-unit to assist in de-escalation; Staff assigned to escort small groups to the hospital’s enclosed garden | NR | NR | NR | NR | The Coping Agreement Questionnaire to determine what upset or agitated patients, how they responded when upset and how they preferred to be treated while on the unit; family were asked for input on effective coping methods | The time that a patient could remain in restraint or seclusion before an additional physician order was required decreased from 4 h to 2 h. | NR | NR
Khadivi 2004 15534024 | NR explicitly; assumed additional staff time required for a) post episode debriefing of the staff and the patient; b) review of each episode by the senior nurse and a physician; and c) continuous nursing monitoring to minimize the duration of episodes of seclusion and restraint | NR | NR | NR | NR | NR explicitly; assumed additional documentation associated with a) new history of inpatient violence to admission form; b) continuous nursing monitoring c) post episode debriefing of the staff and the patient; d) review of each episode by the senior nurse and a physician | NR explicitly; assumed additional time associated with continuous nursing monitoring | NR explicitly; assumed additional time for documentation associated with a) new history of inpatient violence to admission form; b) continuous nursing monitoring c) post episode debriefing of the staff and the patient; d) review of each episode by the senior nurse and a physician | NR
Lewis 2009 19291492 | An “on call witness” and “on call clinician” facilitated the multistep debriefing process | A Family Style Meals program permitted patients and staff to sit and eat together; patient and staff art gallery; framed pictures of staff’s pets on the unit | NR | Patient moved to their room, activity room or empty alcove for use of Comfort Cart | Comfort cart included stress balls, CD players with headphones, aromatherapy, art supplies, musical instruments, karaoke, games, and journal writing supplies. | The Phipps Aggression Screening Tool for identification of patients at risk for violent behavior; The Personal Safety Plan to identify interventions to prevent violence; The Patient Support Sheet to inform the observer of patients under observation on target symptoms, effective interventions, and reportable events; Witnessing program for S/R debriefing which included immediate post event debriefing to gather data on triggers and contributing factors, interventions, and barriers to success. Second stage of program involved a chart review, patient interview and case conference with nursing staff for root cause analysis. | NR | Stage 1 of witnessing program for S/R debriefing occurred immediately after S/R episode, Stage 2 occurred within 24 hours of event. | NR
McDonagh 2019 No PMID | Hired 6 Therapeutic Assistants/ Peer support specialists to put on 4–6 hours of programming a day; involved representatives from other service lines to run group programming including police, human resources, chaplain, nutrition, and voluntary services. | NR | 4–6 hours of programming per day included: Recovery groups (anger, relaxation, etc); SUD/PTSD/Depression groups; Illness Management and Recovery Training; Social Skills Training; Recreation Therapy; Nutrition group; Safety outside the hospital; Occupational/CV building; Oral Hygiene; Non-secular groups; Various entertainment activities; VA Benefits; Discharge planning; Individual/family meetings | NR | NR | Program indicators: Attendance Sheets, Recovery Services Checklist and Various psychometrics (PCL-5, BAM-R, BDI-2, etc); S/R monitoring included documenting day of week initiated, tour of duty initiated, number of episodes per patient, age and gender of patient, staff nurse initiating S/R, any injuries occurring to staff and/or patients, compliance with documentation standards and medication use | NR | NR | NR
Pollard 2007 17102932 | NR | NR | NR | NR | NR | NR | NR | NR | NR
Richmond 1996 8936879 | NR | NR | NR | NR | NR | Data collection form to identify which least restrictive alternative(s) were used and the outcome at the time of intervention with a disruptive patient | NR | NR | NR
Stoll 2022 35650555 | NR | NR | NR | NR | NR | NR | NR | NR | NR
Taxis 2002 11901660 | Core training content delivered by charge nurse to the non-licensed staff in the form of staff meetings and 1:1 sessions; Professional nurse became the coach for non-licensed personnel | NR | Specific programmatic changes made to address the needs of patients with Axis 2 diagnoses with a tendency to engage in self-harming incidents, manipulative, and attention-seeking behaviors | NR | NR | Each event of restraint or seclusion was evaluated by the nurse project manager to determine: (1) appropriateness of the restraint or seclusion, (2) any attempt to use an appropriate, less restrictive alternative prior, (3) care during the incident, and (4) care immediately after the incident; Quarterly report compiled to track incidents and trends by shift, unit, and patient; 23-item audit tool was created that addressed justification of the use of seclusion or restraint, assessment, care during the procedure, care immediately after the procedure and documentation. | NR | NR | NR
Whitecross 2020 32391731 | A multidisciplinery team available on call to manage behavioral deterioration (medical, nursing, psychology, social work, occupational therapy, art and music therapy, and consumer and carer peer support professionals) | NR | NR | NR | NR | NR | NR | NR | NR
Zuehlke 2016 27845534 | 27 interdisciplinary team members consisting of psychiatry, nursing, psychology, social work, peer support, and occupational/recreational therapy; certified peer specialist added to the inpatient unit to meet with patients individually for recovery goal development, resource access and support group facilitation. | NR | Group programming included psychoeducational, recreational, peer-support, and process therapy groups which were increased during the weekdays and added during weekends. | NR | NR | Patients provided a worksheet on goals, objectives, strengths, and preferences which was incorporated into the treatment plan. | NR | NR | NR
APNA Statement, 2018^a^ | Healthcare organizations and their nursing leadership groups must make commitments of adequate professional staffing levels, staff time and resources to assure that staff are adequately trained and currently competent to perform treatment processes, milieu management, de-escalation techniques and seclusion or restraint. | NR | NR | NR | NR | Oversight of seclusion and restraint must be part of an organization’s performance improvement effort and these data must be open for inspection by regulatory agencies. Reporting requirements must be based on a common definition of seclusion and restraint and include specific data requirements. | NR | NR | NR
Ashcraft 2012^a^ | Over 50% of RI staff members are peer support specialists, who through their own experience understand the trauma caused by the use of force and coercion. | Establishment of a noninstitutional environment. In the crisis centers, patients have their own key and home-cooked food; liberal property management processes are employed. Individuals keep their own phones, and families and friends are welcome to visit. | Morning recovery activity designed to create an atmosphere of community by having people share and connect with one another through acceptance rituals. Design and implement, with service recipient input, self-directed programming, including education and self-advocacy to reduce reliance on “compliance oriented” services. | NR | Computer stations provide access to e-mail. | Development of “electronic recovery record” for patients and staff to create electronic recovery and personal wellness plans and jointly document progress in an electronic “wellness journal.” | NR | NR | In outpatient services, case management has been enhanced or replaced by peer recovery coaching.
Clement, 2021^a^ | Physicians, resident physicians, clinical psychologists, registered nurses and advanced practice registered nurses are required to actively participate in plans of care and multidisciplinary teams. The Restraint and Seclusion committee was created to review S/R data for usage and trends. | NR | Provide opportunity for physical activity, distraction, or diversional activities | NR | Play calming music or TV CARE Channel, provide aromatherapy | All orders for restraints and seclusion are entered in the electronic health record using approved hospital order sets. Documentation of restraint and seclusion included a description of circumstances leading to S/R, attempted alternatives with patient’s response, revisions to the plan of care, patient injuries and death related to restraint use. | Assessment and reassessment of the patient regarding the need for restraint or seclusion was required with nurses conferring with providers for continued S/R use before the order expires. For behavioral cases, assessment of physical/psychological status occurred once every 4 hours and every 30 minutes for violent cases. | If an RN initiates/discontinues a seclusion or restraint episode, a licensed independent practitioner must be notified as soon as possible but no later than 1 hour afterward, and an order must be entered in the electronic health record within 6 hours. | NR
Iwamasa, 2017^a^ | Facilities identify a peer support specialist as a seclusion/restraint reduction champion for every unit. Facility leadership ensures adequate inpatient mental health staffing. Inpatient staff should collaborate with quality management staff to access data and run reports used to assess process improvement efforts. Facilities should establish an interdisciplinary data review workgroup. | Home-like non-institutional, and patient-centered environments that imbue healing, familiarity, and a sense of being valued. Environmental design provides opportunities for Veteran relaxation and promotes space for therapeutic staff and Veteran interactions. | Provide patients with meaningful activities through interdisciplinary collaborations including daily treatment planning, motivating patients to educational, therapeutic, and recreational activities. Incorporation of sensory modulation. | Comfort rooms for meditation, music relaxation and sensory modulation. | Equipment for sensory modulation and comfort rooms. | Data relating to S/R episodes must be inputted into the electronic health record. Toolkit provides de-briefing form that can be adopted by staff. Development of a national standardized restraint note. Facilities should consider use of standardized note titles as a process for collecting data while national templates are being developed. | NR | Debriefing must take place within 24–48 hours after the actual event. | NR
VA Northern California HCS^a^ | Charge RN and/or an attending psychiatrist act as clinical consults when staff are concerned about a patient’s behavior or potential for a behavioral emergency. The Code Green team leader has the most knowledge of the patient/situation and/or has the most training. If a therapeutic containment is to occur, at least 3 team members are required. | NR | NR | Use of a quiet room, which is a safe area for enhanced monitoring of patients with escalating anxiety or aggression. | NR | A “Code Green Response Report” is completed in the electronic health record within 48 hours of the incident. The template includes all pertinent information related to the behavioral emergency response. | NR | NR | NR
Wale 2011^a^ | New job title of Behavioral Health Associate who receives extensive crisis prevention and de-escalation training and performs some duties that had been assumed by hospital police. | NR | NR | NR | Purchase of sensory modulation equipment for each inpatient psychiatric unit which included rockers, weighted blankets and vests, and a rolling cabinet in which to store them. | Psychiatric emergency assessment form to be used in all the Psychiatric Emergency Services. This includes a trauma assessment, patient preferences regarding effective calming measures, triggers for agitation, and preferences regarding S/R use. Monthly data submissions to the corporate office are required. | NR | NR | NR

Notes.

a Protocol without evaluation study results.

35 Castle DJ, and Alderton D. (2003) Management of acute arousal in psychosis. In: Castle DJ, Copolov DL, Wykes T. (eds). Pharmacological and Psychosocial Treatment in Schizophrenia. London: Martin Dunitz, pp. 89102.