# APPENDIX H PROTOCOL DETAILS

Author, Year, Country, Design | Producer | Label | VA Protocol | Methods to Produce Protocol | Hypothesis | Intervention Function Content
Hospital/Unit Restructuring
Hochstrasser, 2018, Switzerland, Pre-post | Department of Adult Psychiatry, University of Basel | Open-door policy with recovery oriented care | No | Not explicit; cite previous evidence | An open-door policy will reduce frequency of seclusion and forced medication | Environment:; - Six previously closed psychiatric wards were permanently opened in August 2011; - Processes for monitoring seclusion and forced medication; - Additional changes included more patient-centered and recovery-oriented care, family and caregiver involvement, new psychotherapy concepts, implementation of a primary nursing care delivery model, and other elements
Hochstrasser, 2018, Switzerland, Pre-post | NA | Pre-intervention (practice as usual) | NA | NA | NA | NA
Hunter,1993, United States, Pre-post | Greater Bridgeport Community Mental Health Center | After hospital restructuring | No | Response to staffing shortages and shifts in patient population. Modeled off the Massachusetts Mental Health Center day hospital-inn program. Various consultations and meetings at all levels of the hospital (staff/management, units, disciplines) | NR | Environment:; - Two 22-bed locked wards were transformed into an unlocked day hospital program, transitional residential program, and intensive care unit with close monitoring and 24-hour nursing care. Patients are triaged to the appropriate level of supervision and nursing care.; - Residential program is supervised, activities designed to prepare patients to return to the community.; Education:; - Day hospital patients provided education on how to administer their own medications.; Incentivization:; - Intensive unit has clearly defined privileges (not specified); Restriction:; - Therapeutic environment of intensive unit designed to create a structured social milieu with clear expectations.
Hunter,1993, United States, Pre-post | NA | Before hospital restructuring | NA | NA | NA | NA
Jenkins, 2014, United Kingdom, Pre-post | NHS mental health hospital | Purpose built psychiatric intensive care unit | No | Three years prior, an independent assessment by the Psychiatric Intensive Care Advisory Service (a collaboration between the National Association for Psychiatric Intensive Care Units and the Royal College of Psychiatrists’ Center for Quality Improvement) highlighted environmental difficulties within the old unit, and recommended development of a new ward. Specific methods to design new ward not reported. | It was hypothesized that a new and improved ward environment would be associated with a reduction in arousal and aggression levels overall as measured by formal reports and continuous monitoring records. | Environment:; - Ensuite facilities created for bedrooms with separate Section 136 facilities (areas to assess patients detained by the police); - Gender-specific areas and a seclusion area conforming to Department of Health guidelines; - Seclusion area located more proximally to the nursing station; - Greater access to therapeutic activity space with a designated activities room and development of specific visiting areas; - Increased levels of visibility as measured by all areas of the ward being visible from the staff base, clear lines of sight and observation systems available in all doors and windows; - Increased privacy for patients as all bedrooms are singles
Jenkins, 2014, United Kingdom, Pre-post | NA | Old unit | NA | NA | NA | Environment:; - Furniture was used to partition bedrooms in an attempt to achieve privacy in shared bedrooms
Rohe, 2017, Germany, Pre-post | University Hospital in Tübingen | Architecturally positive redesign | No | Response to structural and therapeutic limitations of former unit built in 1894. Specific methods used to inform design of new building not reported. | NR | Environment:; - A new building with floors able to serve as open or closed wards, design features to allow natural light in rooms, warm/light tones were used for coloring to increase feelings of warmth and friendliness.; - Areas with open space, large lounge, and social areas
Rohe, 2017, Germany, Pre-post | NA | Pre-intervention (practice as usual) | NA | NA | NA | NA
Staff Education and Training
Bowers, 2008, United Kingdom, Concurrent | City Nurses project | City Nurses intervention – escalation training | No | Replication study of City Nurses project which showed significant reductions in patient aggression, conflict, absconding and self-harm and improvements in ward atmosphere and nurse-patient interaction (Bowers et al 2006,^4^ Brennan et al. 2006,^5^ Flood et al 2006).^6^ | Increases in staff appreciation of patients, skills in managing patients, and rules and routines of ward life is associated with reduced conflict and containment. | Persuasion:; - Changes and the methods by which they were achieved were negotiated with staff, with feedback on outcomes periodically provided to the wards; - Appointed City Nurses worked with wards to increase staff’s positive appreciation of patients.; Modeling:; - Two City Nurses clinical experts worked with the wards’ staff 3 days per week to demonstrate low-conflict, low-containment, high-therapy nursing.
Bowers, 2008, United Kingdom, Concurrent | City Nurses project | Concurrent control (practice as usual) | NA | NA | NA | NA
Bowers, 2008, United Kingdom, Concurrent | City Nurses project | Pre-intervention (practice as usual) | NA | NA | NA | NA
Forster, 1999, United States, Pre-post | John George Psychiatric Pavilion | Staff training | No | Multidisciplinary local hospital work group consisting of physicians, psychologists, nurses, social workers, and administrators, to evaluate hospital policy regarding the use of S/R. The committee met biweekly to develop policy recommendations. | Structured S/R programs including interdisciplinary committees and mandatory staff education are associated with a reduction in S/R by shaping staff attitudes towards less restrictive alternatives. | Education:; - The use of S/R was added to the weekly staff meeting agenda.; Persuasion:; - Policy changes received the full support of the hospital administration.; - Administrators participated in training sessions and emphasized that the goal of the program was to reduce S/R and reduce staff injuries.; - Progress of the effort was disseminated hospital wide.; Training:; - Mandatory full day trainings all staff with any patient contact. The course had 3 goals: (1) awareness of the factors leading to patient agitation and violence; (2) promote the knowledge/use of less restrictive measures; and (3) to increase safe staff reactions to violence.; - The program emphasized optimal containment techniques practiced to minimize the risk of patient or staff injury. Inappropriate uses of restraint were discussed, and participants role-played verbal interventions as less restrictive alternatives to physical containment.
Forster, 1999, United States, Pre-post | John George Psychiatric Pavilion | Pre-intervention (practice as usual) | NA | NA | NA | NA
Haefner, 2021, United States, Pre-post | Department of Defense (DoD) and the Agency for Healthcare Research and Quality | De-escalation training (TeamSTEPPS) | No | TeamSTEPPS integrates teamwork in the delivery of health care designed to improve patient safety in high-risk environments. Jean Watson’s Theory of Human Care (Watson, 2012)^7^ formed the framework of the project. | TeamSTEPPS moves nursing staff away from using seclusion by using verbal de-escalation and encourages patients to regain emotional control and reduce aggressive behavior | Education:; - Posters summarizing the TeamSTEPPS training placed at the nurses’ station, the staff lounge, and the report room.; - Nurses received a laminated card with the de-escalation process to attach to her/his identification badge.; Persuasion:; - Unit leadership communicated support of the project.; - Staff were encouraged to use verbal de-escalation to manage aggressive behavior rather than seclusion.; - Staff were encouraged to have a more authentic engagement with the patients to reduce patients’ aggressive behavior.; Training:; - Two-step education program aimed at increasing the nurses’ knowledge of verbal de-escalation. Three self-learning TeamSTEPPS computer modules followed by in-class demonstrations of de-escalation techniques.
Haefner, 2021, United States, Pre-post | Department of Defense (DoD) and the Agency for Healthcare Research and Quality | Pre-intervention (practice as usual) | NA | NA | NA | NA
Sensory Modulation
Lloyd, 2013, Australia, Concurrent | Queensland Health Seclusion and Restraint Committee | Sensory modulation room | No | SM room was designed in following specifications described by Champagne and Stromberg (2004)^8^ and implemented in an acute inpatient setting following the recommendation of the Queensland Health Seclusion and Restraint committee. | 1) Patients would report reduced distress after use of the SM environment.; 2) The unit in which SM was introduced would have reduced frequency and duration of seclusion for the period after the introduction of SM compared with the period prior to the introduction of SM whereas the twin ward where SM was not available would show no such change | Education:; - Provided staff education and exposure to the SM room.; - An SM Open Day was held to introduce patients to SM with opportunity to experience various modalities within the approach.; Persuasion:; - Staff / patients were encouraged to use the SM for early intervention when they became aware of increasing patient distress.; Training:; - Phase 1 included an SM Open Day where patients and staff were introduced to SM; Phase 2 was basic SM training provided to ward staff over several weeks; Phase 3 included on-going one-on-one coaching with a trainer made available to staff by appointment.; Environment:; - A psychiatric intensive care room was converted into a SM room which included equipment and stimuli.; Enablement:; - Access and modification to SM room was tailored to patients following a post-admission sensory screen to identify the sensory stimulation likely to be calming.; - Patients themselves or staff could request use of the SM room.
| | Pre-intervention (practice as usual) concurrent control | NA | NA | NA | NA
Cummings, 2010, United States, Concurrent | New Hampshire Hospital | Comfort room | No | Hospital leadership aimed to reduce the use of S/R. The comfort room project started from suggestions from a patient and a staff member. A quality improvement team was formed to oversee the project. | The addition of a comfort room will reduce the use of S/R. | Education:; - Patients shown the comfort room on admission.; Persuasion:; - Patients are encouraged to use the room as needed and; - bring their own music into the room.; - Nursing staff at the unit were asked to make suggestions to hospital leadership on project implementation.; - Nurse managers empowered nursing staff to assist patients in managing their distress without the use of seclusion or restraint.; Restriction:; - Staff may enter the comfort room any time a patient demonstrates unsafe behavior.; - Comfort room monitored by staff via video.; Environment:; - Comfort room door locked from the outside to allow patients to leave the room at will.; - Comfort room walls painted light blue and decorated with wallpaper and seascape artwork. Dimmer light switch allowed patients to control brightness of the room.; - Multisensory reclining chair; oak entertainment center with television, DVD/VCR and CD player; calming music; books, puzzles, weighted blankets, stress balls and magazines; Enablement:; - When a patient shows signs of distress, the nurse enters a dialogue with the patient to determine the meaning of the behavior. If the patient is in distress, then the nurse may offer the comfort room as a first step in helping the patient progress to a calmer space.
Cummings, 2010, United States, Concurrent | | Concurrent control (practice as usual) | NA | NA | NA | NA
Cummings, 2010, United States, Concurrent | | Pre-intervention (practice as usual) | NA | NA | NA | NA
Azuela, 2018, New Zealand, Pre-post | Dissertation produced at the Auckland University of Technology | Sensory modulation room | No | The SM program was designed based on existing guidelines (Azuela & Robertson, 2016;^9^ Champagne, 2008;^10^ Sutton & Nicholson, 2011).^11^ | NR | Persuasion:; - Project champions lead the implementation of SM room and had regular contact with the research team.; - Project champions were linked with a peer support group.; Training:; - SM training focused on knowledge of clinical principles; therapeutic use of self; use of assessments; selection of sensory modulation activities; displaying supportive attitudes when using a sensory room; and development of personal safety plans with service users.; Environment:; - SM tools included (eg, weighted blankets, stress balls, scented sprays, and music player); - The units received support in the setting up of SM rooms and other environmental modifications within the units.
| | Pre-intervention (practice as usual) | NA | NA | NA | NA
Novak, 2012, Australia, Pre-post | Study Researchers | Sensory room | No | The theoretical basis for sensory rooms emerged from the trauma-informed care, sensory modulation, selfmanagement and recovery literature.^12^ Authors cited the design followed “best practice principles”^13^ | The introduction of the sensory room would: (1) reduce distress reported by consumers who used the room; (2) reduce disruptive and disturbed behaviors demonstrated by consumers who used the room; and (3) reduce rates of seclusion and aggression on the unit. | Education:; - Staff were educated about the room; - Consumers were routinely educated about the room and encouraged to use it when they felt distressed or needed ‘time-out’; Persuasion:; - Staff encouraged to offer time in the room to patient at the first sign of distress or agitation.; - Patients encouraged to use the room when they felt distressed; Environment:; - An existing interview room was converted into a sensory room. The design included a homely environment with scenic pictures, comfortable furnishings and a range of sensory modulation items including weighted blanket, music, magazines/books, rocking chair, scents and a fit ball
Novak, 2012, Australia, Pre-post | NA | Pre-intervention (practice as usual) | NA | NA | NA | NA
Sivak, 2012, United States, Pre-post | Delaware Psychiatric Center | Comfort room | No | The New York Office of Mental Health website (MacDaniel, 2009)^14^ details specific information in the development of comfort rooms which was used as a template. | Use of the comfort rooms would be effective in decreasing client behaviors that could result in the use of seclusion or restraint. Within 4 months of instituting the comfort rooms, there would be 0 use of S/R at the hospital. Within 4 months of instituting the comfort rooms, there would be a 50% reduction in client-to-client assaults and self injurious behavior. | Education:; - Hospital administrators formed a committee, presented the initiative to internal / external stakeholders; - Information about comfort rooms shared via newsletters; - Weekly ward meetings with staff and patients to discuss committee progress; - Staff instructed to suggest comfort room use to clients prior to engaging in any behaviors that could result in negative outcomes.; Persuasion:; - Clients reminded of the importance of keeping the comfort room in good condition.; - Staff suggest patients use comfort room prior behaviors that led to seclusion or restraint.; - Policies governing the use of comfort rooms were developed with agreement of the patient committee members.; Incentivization:; - Contest to name the comfort room. Winner received $5 coupon for the hospital’s canteen and acknowledged publicly.; Restriction:; - Patients read the comfort room agreement form and initial the form prior to use. If unable/unwilling to initial the agreement form the use of the comfort room was not allowed.; Environment:; - Wall murals voted by patients painted in each room; - Chalkboard painted walls in each room to enable drawing; - Drop ceilings to decrease noise level; light panels with sky scenes to improve ambiance; - Recliner, rocking chair, foam chair, lap desk, television and DVD player, drawing tools, paper games and puzzles, aromatherapy; Enablement:; - Client survey to identify items to include in the comfort rooms; - Clients could volunteer to use the rooms for up to 30 minutes when they feel anxious or angry.
Sivak, 2012, United States, Pre-post | Delaware Psychiatric Center | Pre-intervention (practice as usual) | NA | NA | NA | NA
Smith, 2013, United Kingdom, Pre-post | Study Researchers | Sensory Room | No | Based on prior evidence that sensory rooms can reduce the use of seclusion on inpatient units and result in decreased patient distress. Introduction to sensory room occurred after consultation with both staff and patients. | NR | Environment:; - The sensory room has light blue painted walls, laminate flooring, and 1 window which has a black out roller blind.; - The following equipment was placed in the room: a large floor mounted bubble tube, an optic mat, a light/image emitting projector, 2 lying bean bags, 2 sitting bean bags, a variety of cushions, an iPod dock/iPod, and drawers containing magazines, stress relief toys, chewing gum, and educational materials promoting relaxation and healthy living.
Smith, 2013, United Kingdom, Pre-post | NA | Pre-intervention (practice as usual) | NA | NA | NA | NA
Zimmermann, 2020, United States, Pre-post | Dissertation produced at Brandman University and implemented at Mohave Mental Health | Serenity room | No | The serenity room was based on the comfort room model, established from The Theory of Comfort (Alligood & Tomey, 2010).^15^ | Serenity room decreases the use of S/R in patients who are experiencing increased anxiety, anger, and aggression. | Education:; - 35 staff were provided education on the use of the serenity room.; - Patients made aware of the sensory room as a treatment option; Environment:; - Serenity room was painted, decorated, and furnished with a desk, rocking chair, and oversized bean bag, and sensory items like kinetic sand, stretch balls, and fidget spinners.
Zimmermann, 2020, United States, Pre-post | Dissertation produced at Brandman University and implemented at Mohave Mental Health | Pre-intervention (practice as usual) | NA | NA | NA | NA
Risk Assessment
Abderhalden, 2008, Switzerland, RCT | Developers of the The Brøset Violence Checklist (Almvik &Woods 1999)^16^ | Structured risk assessment (BVC) | No | Implemented validated Swiss version of the Brøset Violence Checklist (BVC) | Risk assessments can reduce the frequency and severity of patient aggression and use of coercive measures. | Education:; - Staff were provided explicit recommendations for interventions based on risk assessment scores.; Persuasion:; - Staff discussed preventive measures with patients from a list provided on the risk assessment form.; - High risk patients received multidisciplinary team consultation to discuss the need for immediate intervention.; Environment:; - A structured short-term risk assessment (BVC) administered during the first 3 days of hospitalization.; - The BVC requires nurses to rate 6 patient behaviors (confusion, irritability, boisterousness, verbal threats, physical threats, and attacks on objects) and to perform an overall subjective assessment of the risk of imminent violence. Ratings were conducted twice daily.
Abderhalden, 2008, Switzerland, RCT | Developers of the The Brøset Violence Checklist (Almvik &Woods 1999)^16^ | Wait-list control (practice as usual) | NA | NA | NA | NA
Abderhalden, 2008, Switzerland, RCT | Developers of the The Brøset Violence Checklist (Almvik &Woods 1999)^16^ | Preference arm (practice as usual) | NA | NA | NA | NA
van de Sande, 2011, Netherlands, RCT | Developers of the The Bnaset Violence (Almvik & Woods 1999)^g^, past trial by Abderhalden et al. (2008), and study investigators | Structured risk assessment (BVC) | No | Implemented BVC. Sought to extend work Abderhalden et al (2008)^17^ by exploring the added value of using the checklist during a patient’s stay in addition to once during admission. | Structured short-term risk assessment can improve clinical decision-making and can result in timely de-escalation actions, avoiding coercive interventions. | Training:; - All psychiatric nurses and doctors on the wards were trained to use the risk assessment instruments.; Environment:; - Patients were monitored daily by nurses using risk assessment scales.; - Daily scales included the Crisis Monitor, BVC and the Kennedy–Axis V (short version) to identify risks of loss of control.; - Weekly scales included the Kennedy–Axis V (full version), the Brief Psychiatric Rating Scale, the Dangerousness Scale and the Social Dysfunction and Aggression Scale were used to evaluate changes in mental state.; - The Crisis Monitor scale ratings were discussed by the multidisciplinary team daily and at weekly clinical meetings.; Environment:; - Risk assessment scales incorporated into short-term clinical decision making, intervention planning and evaluation.; - The Crisis Monitor scores guided discussions on how to deal with observed changes in risks, such as timely verbal de-escalation, behavioral limitsetting, and observation.
van de Sande, 2011, Netherlands, RCT | Developers of the The Bnaset Violence (Almvik & Woods 1999)^g^, past trial by Abderhalden et al. (2008), and study investigators | Control (practice as usual) | NA | NA | NA | NA
Blair, 2017, United States, Pre-post | Developers of the BVC (Almvik & Woods 1999),^18^ supplemented by Hartford Hospital, Connecticut | Structured risk assessment (BVC) | No | Implemented a previously validated risk assessment tool (BVC) in combination with other evidence-based strategies for reducing violence/aggression (eg., staff education, trauma informed care, assessment of S/R practices, etc) | Use of prevention strategies of aggression can reduce use of S/R. | Training:; - Staff completed a 2-day training based on a trauma-informed model of care intended to reduce staff behaviors that can exacerbate “trauma reactions” in patients.; Restriction:; - Physician renewal orders required for S/R increased from 4 to 2 hours.; Environment:; - BVC used daily documentation completed by a physician on arrival and by nursing staff during each shift.; - Introduced new nursing assignments to maximize staff presence in the milieu.; - Required that the Medical Director and the Director of Nursing examine all S/R events.; - Environmental enhancements included assessing the patient’s “sensory diet” on admission to identify personalized coping strategies to reduce aggression.; - Created comfort rooms with calming lights, sensory items, and music.
Blair, 2017, United States, Pre-post | Developers of the BVC (Almvik & Woods 1999),^18^ supplemented by Hartford Hospital, Connecticut | Pre-intervention (practice as usual) | NA | NA | NA | NA
Clarke, 2010, Canada, Pre-post | Developers of the The Brøset Violence Checklist (Almvik &Woods 1999) | Structured risk assessment (BVC) | No | Implemented previously validated risk assessment tool (BVC) developed by Almvik &Woods (1999)^19^ | The BVC may assist health-care workers in the prevention of or reduction in the impact of violence through an early identification of patients with the potential for violence for which least restrictive interventions can be employed. | Education:; - Participating staff members were oriented to the use of the risk assessment tool by the research nurse in brief 15-min sessions, either in a group or individually.; Environment:; - BVC was completed by general duty nursing staff on each shift for the first 72 hours of admission. Nurses completed a form for each patient assigned to them on that shift.; - Nurses involved in each aggressive incident were interviewed post incident to determine whether it could have been prevented.
Clarke, 2010, Canada, Pre-post | Developers of the The Brøset Violence Checklist (Almvik &Woods 1999) | Pre-intervention (practice as usual) | NA | NA | NA | NA
Harrington, 2019, Australia, Pre-post | Study researchers | Risk assessment (Clinical Risk Management Initiative; CRMI) | No | A model for managing clinical risk to replace standard visual observation. This model was based on clinical engagement principles and was developed using a participatory action research framework involving staff and consumer focus groups. The model was piloted and refined before full implementation. | The model would be associated with a decrease in adverse events and an increase in staff satisfaction levels. | Education:; - Extensive education program describing changes to patient care and the expectations of staff; - Staff explain to medium risk patients planned management strategies; - The Patient Safety Plan described: possible early warning signs indicating change to risk; possible activities to decrease exacerbation of risk (identified by patient); and management strategies.; Persuasion:; - All clinical staff encouraged to regularly engage with medium risk patients, regular assessment, planning, and prevention; - Patients asked to identify and participate in activities to decrease exacerbation of risk; - Regular staff meetings allowed for feedback to improve the CRMI and to provide support and clarification when needed.; Training:; - Staff trained on how to conduct the risk assessment; Environment:; - The CRMI established a tailored risk review process in which risk assessments were at designed periods. Patients were categorized into ‘low,’ ‘medium’, or ‘high’ risk status. Risk assessments for every patient were documented at weekly for discussion at multidisciplinary clinical review meetings.; - Members of the clinical team performed routine ward checks with low-risk patients every 2–3 hours. Change in mental status or risk was reported to contact nurse or shift leader.; - Medium-risk patients were allocated a contact nurse who was responsible for engaging in regular risk assessment.; - High-risk patients were managed in the High Care Area or in the Low Dependency Unit with 1:1 nursing.; Enablement:; - The patient safety plan was completed in collaboration with patients whenever possible.
Harrington, 2019, Australia, Pre-post | Study researchers | Pre-intervention (practice as usual) | NA | NA | NA | NA
Manning, 2022, United States, Pre-post | Study researchers | Risk assessment (modified Agitation Severity Scale; MASS) | No | Implemented a modified version of the Agitation Severity Scale (Strout, 2011)^20^ (MASS). Modifications were made to allow for rapid clinical assessment and linking the scale to a treatment protocol. | Rapid clinical assessment of agitation can inform clinical decision making to avoid aggressive and violent behavior and reduce involuntary medication administration and S/R practices. | Education; - A list of non-pharmacologic interventions compiled based on published guidelines and with input of nursing staff; Persuasion; - Medication use was encouraged as second line treatment.; - Staff were encouraged to employ behavioral interventions to reduce agitation: speak with patient about frustration, encourage patient to channel feelings into activity, identify wants and feelings, redirect attention and offer choices, encourage relaxation techniques, offer fluids/food, and encourage self-time out.; Training; - Physicians and nursing staff were trained in the use of the MASS and Agitation Treatment Scale.; Restriction; - Seclusion or restraint were only a last resort and required notification of the physician.; - MASS agitation scores determined which interventions were appropriate: very mild score = behavioral intervention; mild score = oral medication; moderate score = intramuscular injection; high score = seclusion/restraint.; Environment; - Treatment protocol incorporated 4 pharmacologic tracks based on agitation score upon admission. Preference was for behavioral intervention followed by oral medication, intramuscular medication and then seclusion or restraint as a treatment of last resort. Seclusion or restraint also required notification of the physician.; - Agitation scores entered directly into the electronic medical record that corresponded with a management strategy.; Enablement; - Patients were encouraged to use coping skills and relaxation techniques
| | Pre-intervention (practice as usual) | NA | NA | NA | NA
Trauer, 2010, Australia, Pre-post | Study researchers | Management of Acute Arousal Program (MAAP): assessment, psychosocial interventions, pharmacological interventions, and debriefing. | No | Developed based on prior research showing that enhanced management of problem behaviors and improved monitoring results in lower rates of seclusion^21^ | The expectation was that there would be a reduction in seclusion in the 6 months of the intervention compared with the 6 months before its introduction. | Education:; - 24 to 48 hours after an episode of MAAP, patients were offered a debriefing with a member of staff who had not been involved in the episode.; - Ward staff were also given manuals and pocket-sized reference materials, and regular opportunities to meet with senior staff to review the operation of the program.; Persuasion:; - Time-out: the patient is asked to go voluntarily to an area in the unit for a specific period of time away from others; - A Practice Development Nurse was appointed for the 6 month implementation to provide training and ongoing support and monitoring.; - Senior clinicians on the ward would ask about the initiation of any MAAP episodes at an informal check-in with shift leaders and staff.; Training:; - All clinical staff were trained in MAAP in 2 sessions. The training included all elements of MAAP and use of the documentation system.; - Training was also provided to new staff as required.; Environment:; - Ward nursing staff initially assessed patients displaying agitated or aggressive behavior using the Fremantle Arousal Scale. According to the level of arousal, a psychosocial intervention was applied, selecting from an ordered list: ventilation, redirection, time-out, restraint, or seclusion; - Each MAAP episode was initiated as required and continued until a low level of arousal was reestablished.; - ‘As required’ or PRN medications could be given at any stage.; Enablement; - Ventilation: patients provided opportunities express fears, frustration anger, anxiety and triggers.; - Redirection: staff explored with the patient solutions to assist them in gaining control including distraction.
Trauer, 2010, Australia, Pre-post | NA | Pre-intervention (practice as usual) | NA | NA | NA | NA
Comprehensive/Mixed
Bowers, 2015, United Kingdom, RCT | Study researchers | Safewards | No | The Safewards Model was developed by Bowers (2014)^22^ to explain variable rates of conflict and containment and identify a large number of ‘staff modifiers’ that can impact on the likelihood of conflict or containment incidents. The model enabled the creation of a list of interventions that could enhance the staff modifiers and thereby reduce conflict and containment rates. Panels of expert nurses, service users, and carers identified the top intervention strategies to be included in pilot studies which were subsequently reduced into a package of 10 interventions. | Wards randomized to Safewards vs control would show fewer conflicts and less constraints defined as (coerced medication, seclusion, restraint, and special observation). | Education:; - Advisory statements (called ‘soft words’) on handling flashpoints were hung in the nursing office and changed every few days.; Persuasion:; - Staff required to say something good about each patient at nursing shift handover.; - Staff encouraged to scan for potential bad news a patient might receive from friends, relatives or staff, and intervening promptly to talk it through.; - Staff provided reassuring explanations to all patients following potentially frightening incidents.; - A display of positive messages about the ward from discharged patients was introduced.; Training:; - A de-escalation model used by the best deescalator on the staff (as elected by the ward) expanded the skills of the remaining ward staff.; Environment:; - Structured, innocuous, personal information was shared between staff and patients (eg., music preferences, favorite films) via a ‘know each other’ folder kept in the day room.; - A crate of distraction and sensory modulation tools to use with agitated patients included stress toys, music players with soothing music, light displays, and textured blankets.; Modeling:; - A de-escalation model used by the best deescalator on the staff (as elected by the ward concerned) expanded the skills of the remaining ward staff.; Enablement:; - Publicized standards of behavior by and for patients and staff were mutually agreed upon.; - A regular patient meeting to bolster, formalize, and intensify inter-patient support
Bowers, 2015, United Kingdom, RCT | Study researchers | Control wards (physical health program) | NA | Wards in the control condition implemented a set of interventions directed at improving staff physical health. Staff on the control wards were told that improvements in their own physical health would lead to them delivering care more effectively, and thereby reduce conflict and containment. | Improvement in physical health was predicted by the Safewards Model to have no impact on conflict and containment. | Education:; - Desk exercise poster placed in ward office; - Staff completed diet assessment and feedback was provided.; Incentivization:; - Staff participated in pedometer-based competitions.; Environment:; - Supplies of health snacks, exercise magazines, and health promotion literature were available in ward offices.; Enablement:; - Linkages to local sports and exercise facilities were made.
Valimaki, 2022, Finland, RCT | Study researchers | VIOLIN (Violence Intervention) | No | Informed by previous research (The EUNOMIA [European Evaluation of Coercion in Psychiatry and Harmonization of Best Clinical Practice] study (Fiorillo 2011)^23^) that developed trainings for professionals on the management of aggressive behaviors and improved communication between community and hospital teams. Present study (VIOLIN) was designed to improve treatment culture and reduce the need for coercive methods. A pilot study was undertaken with staff members, patients, and relatives in 1 hospital ward prior to present study to ensure acceptability, understandability, usefulness, and feasibility of the intervention. | Patient condition, treatment environment and ward culture may affect patient behavior. The use of coercive methods can be prevented with staff education about user-centered, humane approaches as well as collaboration between patients, family members and staff members. | Education:; - Program contents were taught to staff via lectures, seminars, workshops, and site visits.; - Knowledge on evidence-based studies demonstrating how to fill possible quality gaps shared with staff members. Strengths, weaknesses, opportunities, and threats related to unit changes were captured.; - Information packages including intervention materials were made available to staff to support competency.; Persuasion:; - Support available from the project team included monthly monitoring and support calls or emails to prompt and encourage change in staff members.; Training:; - Hands-on-support was provided by the trial team. The contact persons worked with staff to help them gain confidence in the new ideas of the intervention. The understanding of the intervention was reviewed using an interim evaluation.; Enablement:; - Local meetings involving staff members, patients, relatives, and the trial team specified detailed areas to be developed and the specific steps to be taken. Possible barriers and facilitating factors for change were identified.
Valimaki, 2022, Finland, RCT | Study researchers | Control Wards (practice as usual) | NA | NA | NA | NA
Boumans, 2014, Netherlands, Concurrent | Vincent van Gogh psychiatric hospital | Methodical Work Approach | No | The Methodical Work Approach (Coussens 2010; Tiemens et al 2010; Winkelaar 2001)^24^ is part of the professional training of almost all mental health personnel in the Netherlands and Belgium. The approach entails a systematic, transparent, and goal-driven way of working with cyclic evaluation and adjustment of the working process. A new format was developed for the treatment in which problems, goals, and means could be specified per life domain. These life domains were derived from the Camberwell Assessment of Needs Short Appraisal Schedule (Andresen et al. 2000)^25^ and were clustered into a suitable framework with the following domains: daily living activities; social, financial, sexual, or psychiatric problems; and substance-use disorders. A domain ‘existential questions’ was added because of apparent needs in the specific patient group. | Implementation of the Methodical Work Approach would lead to a reduction in the use of seclusion | Education:; - The program included education on the negative effects of coercive measures and feedback to all ward teams about their use of these measures.; Persuasion:; - In the team members’ daily reports, and during meetings and consultations, staff were encouraged to describe their interventions in relation to the goals and means in the life domains listed in the treatment plan.; - All staff members on the ward were actively involved in intervention preparation and were invited to the expert group to redesign the treatment process.; Training:; - Training program included 3 sessions attended by all multidisciplinary team members. During these sessions the principles of the Methodical Work Approach were introduced, and the 5 phases of the treatment process were explained. The procedure for the treatment process, as designed by the expert group, was demonstrated and integrated in the routine of the ward.; - During the first training program the teams started to practice with the formulation of care plans using the Methodical Work Approach and were given feedback on the quality of the plans.; - A second training program of the Methodical Work Approach lasted 3 days and the application of the approach into daily practice was elaborated on and illustrated with examples of patient care.; - The program also included a workshop on the principles of evidence-based practice. The search for means to achieve goals was discussed and nurses learned how to ask ‘answerable questions’, as well as how to execute a search strategy in the literature. Guidelines were given to the nurses for deciding whether and how to use the evidence they found to modify their plans.; Environment:; - The Methodical Work Approach involves 5 phases: (i) translation of problems into goals; (ii) search for means to realize the goals; (iii) formulation of an individualized plan by matching specific means to individual needs and preferences; (iv) implementation of the plan; and (v) evaluation and readjustment. The 5 phases of the Methodical Work Approach can apply to several aspects of the treatment process: the therapeutic relationship, the treatment process, and/or the conditions for treatment.; Enablement:; - A key element of the Methodical Work Approach is the individual plan, which describes the goals of the patient, as well as the specific means to achieve these goals. Both goals and means are chosen in line with the patient’s individual needs and references. The resulting procedure was as follows: the coordinating nurse assisted with the formulation of patient goals for specific life domains. When the family was involved, the coordinating nurse enquired about the family’s vision on the goals of the patient and invited the family to participate in the treatment process. The multidisciplinary team then met with the patient and family to outline the short- and long-term goals and the means to achieve these. All decisions made at the meeting were recorded in the treatment plan. Progress was regularly evaluated and discussed with the patient and family. When delays were observed, possible causes were sought at all levels of the treatment process, and adjustments to the plan made accordingly. At follow up meetings the team evaluated, together with the patient and family, whether the goals had been reached and whether continuation of treatment at the ward was still indicated.
Boumans, 2014, Netherlands, Concurrent | Vincent van Gogh psychiatric hospital | Control (practice as usual) | NA | NA | NA | NA
Noorthoorn, 2014, Netherlands, Concurrent | NR | Intervention | No | Based on the assumption that seclusion did more harm as being traumatic and the assumption that restraint in general reflected more the relation between staff and clients, a project was started to abandon seclusion and diminish other forms of restraint in three years. The project was accompanied by a process evaluation built on and supported by a project leader and a researcher to supply data to the staff of the experimental ward. | NR | Training:; - Team training aimed at prevention of aggression, dealing with conflict and restoring relationship with patient. Individual coaching provided as follow-up to team training.; Environment:; - A proactive approach in detecting behavior preceding aggression was implemented by using information from the patient, the family, and community nurses in developing means to deal with patient behavior, described within a specified signaling plan.; - Family participation was appreciated as a main component of treatment.; - At regular intervals researchers provided feedback on the numbers of restraint measures implemented to the team.; - After an involuntary admission, dangerousness criteria as formulated within the home environment were re-evaluated within the context of the admission.; - Team cohesion was stimulated by frequent team meetings.; - During first admission, information was gathered to compile specified signaling plans (ie, plans aimed at early detection of behavior preceding aggression).; Restriction:; - Clear boundaries and limitations with respect to acting out behavior were communicated at admission.; Enablement:; - Agreement with the patient on treatment and signaling plan was valued as an important means in early detection of behavior preceding aggression.; - All staff members had an important input in developing treatment plans.
Noorthoorn, 2014, Netherlands, Concurrent | NR | Control (practice as usual) | NA | NA | NA | NA
Blair, 2015, USA, Pre-post | Salem Health Psychiatric Center | Engagement Model | No | In 2001, based on the Sanctuary approach of Sandra Bloom (1997), the authors’ hospital initiated the Engagement Model (Murphy & Bennington-Davis, 2005). The goal of this model was to implement an acute care, inpatient psychiatric recovery model that provided a safe and healing environment founded on trauma-informed care. Positive therapeutic alliances would be built with patients and efforts were directed toward individualization of treatment, with maximization of patient involvement. Management and staff desired to shift power and control from staff to patients as much as possible and reduce or eliminate the need for S/R. | NR | Education:; - Community meetings are an opportunity to educate patients about the trauma-informed model of care.; Persuasion:; - Spontaneous interventions are welcomed and staff are encouraged to think “outside the box” when exploring alternatives.; Training:; - Annual Professional Assault Crisis Training required for all psychiatric, ED, float pool, and Security Services staff members.; - Security staff earn mastery in the use of de-escalation techniques.; Environment:; - Admission screening tools provide information about individual patient trauma history, triggers, history of assault or aggression, and strategies the patient finds helpful for self-calming.; - Twice daily community meetings are led by patients with staff guidance to discuss community expectations, issues, and concerns. Non-threatening, recovery-focused discussion questions are asked. The community guidelines and nonviolence policy are read at each meeting.; - A special community meeting can be to address brewing problems or debrief an incident that has already occurred. These meetings can be requested by staff or patients.; - Staff have developed a more defined low stimulus protocol for intrusive or disruptive patients, increased the use of spontaneous staff “huddles” for problem solving, and promoted greater individual initiative in creating early self-management plans for challenging cases.; - Management team performed a root cause analysis on all incidents of S/R, with subsequent all-staff review in a nonjudgmental forum.; - One staff member remains with a more challenging patient, engaging with him or her on a consistent basis until he or she begins to stabilize.; - Rooms may be made available where patients can go for a quieter atmosphere.; - Groups focused on active practice of relaxation or distraction techniques may be held in side rooms.; - Staff have been offered the opportunity to eat free family-style meals with patients. Staff receive traditional 30-minute lunch breaks at a different time.; - Staff spend less time in the nursing station or offices. An increased staff presence in the milieu can take the form of simply sitting and chatting with patients or reading a newspaper in the day area during downtime.; - Two small side rooms are used as patient television viewing areas, so that the main day area promotes conversation and personal interactions.; Enablement:; - Managers offer themselves as resources rather than as the ultimate decision makers.; - Ongoing recognition of unit successes and individual staff initiatives related to improved patient care is encouraged.; - Staff to feel empowered in terms of decision making when acute situations occur.; - Therapy staff have met twice per week with each patient to discuss patient-identified strengths, goals, progress, and treatment team recommendations.; - When requests are reasonable and not dangerous, they are included in choice options including allowance for pet visits, use of music/headphones at times that are outside of the normal unit guidelines, loosening of American Dietary Association restrictions, authorized use of computers, or supervised use of guitar or karaoke equipment.
Blair, 2015, USA, Pre-post | NA | Pre-intervention (practice as usual) | NA | NA | NA | NA
Dickens, 2020, Australia, Pre-post | Study researchers | Safewards | No | Safewards intervention was developed by Bowers et al. (2014).^26^ A plan for Safewards implementation was devised with a group of select staff from each participating ward who volunteered or were nominated by the unit manager to facilitate the application of the interventions on their unit. | The introduction of Safewards would be associated with significant reductions in reported (i) conflict; (ii) serious conflict (physical violence); (iii) containment; (iv) highly coercive containment (seclusion, restraint, forced medication) after controlling for potential confounding variables; and (v) with significant improvements in the measured violence prevention climate. | Education:; - Safewards was introduced to nursing staff via hour long ward in-service sessions.; Training:; - 12-week implementation phase included train-the-trainer sessions for clinical nurse consultants, introductory in-service education sessions, and educational materials were provided.
Dickens, 2020, Australia, Pre-post | Study researchers | Pre-intervention (practice as usual) | NA | NA | NA | NA
Hellerstein, 2007, United States, Pre-post | New York State Psychiatric Institute (NYSPI) | Comprehensive intervention | No | In the year 2000, NYSPI initiated an institute-wide program to reduce rates of restraint and seclusion. A multidisciplinary group of physicians, nurses, mental health aides, and quality management personnel convened to review the literature, identify characteristics of NYSPI patients who were restrained or secluded, and to compare NYSPI with other institutions to determine factors contributing to higher rates of restraint and seclusion use. | Intervention would 1) reduce the number of patients placed in restraint or seclusion 2) reduce the length of time patients spend in seclusion or restraint and 3) achieve these reductions without increasing adverse outcomes as measured by patient-related staff injuries, elopements, and fights and assaults. | Education:; - Clinical staff educated about appropriate indications for S/R. Staff discussions focused on situations that could potentially require the use of S/R and how clinicians could find alternatives.; - The Coping Agreement Questionnaire collected information on what agitates patients, how they respond when upset, and how they would prefer to be treated while on the unit. Also elicits family input on coping methods.; Persuasion:; - Staff encouraged to discontinue restraints or open the seclusion room door if the patient was sleeping.; - Clinical staff used individual patients’ responses on the Coping Agreement Questionnaire to help them find ways to deal with agitation.; Restriction:; - The time a patient could remain in S/R after an initial physician’s order before a second order was required was decreased from 4 to 2 hours.; - Clinical director must evaluate all patients who had 2 or more consecutive episodes of restraint or seclusion.; - Clinical practices were changed, so that if security personnel were called to deal with an agitated patient restraint and seclusion were no longer an automatic result.; Environment:; - Additional staff were assigned to escort small groups of patients to the hospital’s enclosed garden.; - Staff members could escort an individual patient off-unit if it was thought to be likely to help him or her become calmer.; Enablement:; - Policies were changed to allow for off-unit privileges earlier during hospitalization.
Hellerstein, 2007, United States, Pre-post | New York State Psychiatric Institute (NYSPI) | Pre-intervention (practice as usual) | NA | NA | NA | NA
Khadivi, 2004, United States, Pre-post | Bronx Lebanon Hospital Center | Comprehensive intervention | No | Designed to be compatible with the mandates of the Joint Commission on Accreditation of Healthcare Organizations (JCAHO) to respect patients’ autonomy by minimizing the use of S/R in psychiatric and nonpsychiatric settings. | NR | Education:; - Staff education provided on early recognition of agitation and clinical intervention.; Training:; - Staff trained to recognize of signs of agitation among patients and engage in early clinical intervention.; N.B. All staff members had previously been trained on assault prevention measures; however, this training varied and specific training on violence prevention was not given during the study period.; Environment:; - History of inpatient violence was collected within the admission form.; - Continuous nursing monitoring was implemented to minimize the duration of episodes of S/R.; - Post episode debriefing of the staff and the patient took place with a review of each episode by the senior nurse and a physician.
Khadivi, 2004, United States, Pre-post | Bronx Lebanon Hospital Center | Pre-intervention (practice as usual) | NA | NA | NA | NA
Lewis, 2009, United States, Pre-post | Henry Phipps Psychiatric Clinic | Crisis Prevention Management (CPM) program | No | A group of psychiatric nurses created an evidenced-based performance improvement program informed by the Public Health Prevention Model (Huckshorn, 2004).^27^ The model uses primary, secondary, and tertiary prevention strategies to decrease the use of S/R. A committee comprised of nurses from all of the inpatient units developed a vision for patient care delivery. | Changing the culture of patient care is believed to be a necessity for any real S/R reduction efforts. | Persuasion:; - Each unit had nurses who “championed” the new model, reinforced that S/R hinder recovery; pushed peers to become more proactive and creative with [alternative] interventions.; - All staff in the department attended a day-long workshop designed to facilitate cultural change through presentations, discussion, and staff input into the development of various aspects of the model.; - Signs were posted on the unit and verbal reminders were given to move staff closer to the patients.; - When implementing the Comfort Cart the nurse assisted the patient and stayed with them to offer support, participate, and offer feedback.; Training:; - Psychiatric Emergency Training included information on primary, secondary, and tertiary interventions. Presented performance improvement measures, aspects of relationship building, verbal de-escalation techniques, and research findings.; - Nurse Managers were trained to serve as “on-call clinicians” for debriefing process.; Environment:; - Daily Safety Focused Community Meetings were modified to add specific content stressing the importance of feeling and being safe in the milieu.; - The Phipps Aggression Screening Tool was implemented at admission to identify individuals at increased risk for violent behavior. Staff utilized the responses to plan care.; - Twice a day, several hours after shift report, all nursing staff met briefly to discuss any current or potential safety issues.; - A witnessing debriefing process included an immediate post event debriefing led by the “on-call witness.” to gather data regarding the triggers and contributing factors in the event, what interventions were attempted, and what barriers were present to impede the success of the interventions. A chart review, a patient interview, and a case conference with the nursing team involved in the incident occurred. The conference was used to identify contributing factors, alternative actions, and changes necessary to prevent future events. A key component of a successful witnessing process is establishing a non-punitive environment where staff is encouraged to share their thoughts, feelings, and opinions.; - Staff can implement and evaluate interventions more effectively by sharing what is (or is not) working well for a patient.; Enablement:; - The Personal Safety Plan is initiated on admission to gather information delineating the patient’s response to distress and identify what interventions will be most helpful for him to stay in control. It sets the expectation that the individual is a partner in his health care team. If the individual was unwilling to participate, information was obtained from family, care providers, or previous records.
Lewis, 2009, United States, Pre-post | Henry Phipps Psychiatric Clinic | Pre-intervention (practice as usual) | NA | NA | NA | NA
McDonagh, 2019, United States, Pre-post | Ralph H Johnson VA Medical Center | Recovery-oriented programming | Yes | Identified reducing S/R is a national priority and movement towards recovery-oriented/patient centered care as a VHA priority | NR | Education:; - Staff education provided; - Recovery-oriented curriculum developed including self-help resource book/worksheet; Persuasion:; - Frontline staff were included from the beginning in policy design/implementation.; - Established a “commitment to resilience” to inspire innovative solutions within a dynamic environment.; - Developed a “pre-occupation with failure” and did not accept the current S/R rate; Training:; - Various trainings provided to patients (eg., illness management, recovery training, social skills training); Environment:; - Therapeutic Assistants were hired.; - Coordination with various departments to put on 4–6 hours of daily programming (Nutrition service, VA police, Human resources, Dental Service, Chaplin Service, Voluntary service, SC State Department of Veteran’s Affairs); - Programming included recovery groups, substance use disorder/post-traumatic stress disorder/depression groups, illness management and recovery training, social skills-training, recreation therapy, nutrition group, safety outside the hospital, occupational,, oral hygiene, non-secular groups, various entertainment activities, VA benefits, discharge planning and individual/family meetings.; Modeling:; - Deference to expertise as staff relied on local subject matter experts for guidance/Integration of peer support specialists
McDonagh, 2019, United States, Pre-post | Ralph H Johnson VA Medical Center | Pre-intervention (practice as usual) | NA | NA | NA | NA
Pollard, 2007, United States, Pre-post | VA Puget Sound Health Care System | Comprehensive intervention | Yes | Local quality improvement initiative (formal and informal) initiated in response to the Joint Commission on the Accreditation of Healthcare Organizations (JCAHO) 2000 standards^28^ for the utilization of S/R | NR | Education:; - Facility policies and procedures for the use of S/R were updated to reflect the emphasis on expanded leadership involvement in S/R usage.; - Videotapes were prepared to serve as stimuli for discussions regarding risks of restraint, alternatives to restraint, and the senior leadership commitment to a restraint free environment.; Persuasion:; - Explored staff concerns about the new standards through informal discussion and focus groups.. Positive feedback provided to staff from both senior unit management and facility leadership on the use of alternatives.; - Aggregated and trended data were presented and discussed monthly at the facility clinical executive committee meeting.; - Staff discussions regarding alternatives to the use of S/R occurred.; Environment;; - Mental health and nursing leadership were tasked with reviewing all episodes of behavioral restraints for appropriateness and for meeting specified documentation requirements. The committee was also tasked with identifying of opportunities for improvement of care and patient safety.
Pollard, 2007, United States, Pre-post | VA Puget Sound Health Care System | Pre-intervention (practice as usual) | NA | NA | NA | NA
Richmond, 1996, United States, Pre-post | Fort Lyon VAMC | Comprehensive intervention | Yes | In November 1991 the medical center implemented a facility wide training program on prevention and management of disturbed behavior with the aim of reducing the number of S/R hours and reducing job-related injuries due to managing assaultive behavior. | NR | Education:; - Nursing staff educated on the need to use least restrictive alternatives to keep patients out of S/R.; Persuasion:; - Staff were instructed to use and document the effectiveness of least restrictive measures on all patients exhibiting disruptive behavior.; Training:; - Staff training on prevention and management of disturbed behavior included early assessment of disrupted behavior, intervention using least restrictive alternatives and a team approach to using physical restraint if least restrictive alternatives are ineffective.; - Alternatives included: one-to-one verbal intervention, time out, relaxation techniques, physical/diversional activity, changing the medication regimen or medication as needed.
Richmond, 1996, United States, Pre-post | Fort Lyon VAMC | Pre-intervention (practice as usual) | NA | NA | NA | NA
Stoll, 2022, Switzerland, Pre-post | Study Researchers | Moral case deliberation | No | Used the framework of clinical ethics support to help practitioners consider the use of coercion by determining the morally most justifiable course of action (Hem et al., 2015).^29^ Moral case deliberation, a form of clinical ethics support, was specifically adopted for the intervention (Molewijk et al., 2008)^30^ | With monthly moral case deliberation 1) formal coercive measures in general and seclusion, isolation, and coerced medication in particular will become a) less frequent and b) less intense; and 2) health practitioners will show higher moral attentiveness, estimate the intensity of coercion more accurately, exhibit a more negative attitude towards coercion, and disapprove coercion more often than before. | Persuasion:; - Monthly moral case deliberation meetings occurred in which staff addressed concrete, past, or anticipated moral challenges related to coercion.; - Health practitioners meet to reflect collaboratively and systematically on concrete clinical cases.; - Moral case deliberation took approximately 60 minutes and was structured by one of several conversation methods, chosen according to the purpose of the session. Methods could focus on the process (eg, self-refection, teambuilding, skills training) or the product (eg, solutions, compromises, answers).; - Instead of giving normative recommendations, a trained facilitator focused on the quality of the deliberation process and the meaningfulness of the moral issues.
Stoll, 2022, Switzerland, Pre-post | Study Researchers | Pre-intervention (practice as usual) | NA | NA | NA | NA
Taxis, 2002, United States, Pre-post | Study researchers | Comprehensive intervention | No | Intervention developed via discussion groups with nurses and a review of the literature with concerns including (1) lack of alternatives employed prior to restraining patients, (2) a culture that was resistant to change and (3) issues regarding safety when implementing restraint and seclusion. Audits of events of S/R to alternatives identified. Leadership sought to create a culture shift ‘from control to collaboration’ to reduce use of S/R. A comprehensive change program was recommended. | NR | Education:; - Staff education included lectures, skill-building interactive activities, and group discussions. Content included collaboration and de-escalation techniques, 1:1 discussions, diversional activities, ethical considerations, use of medication, and skills for improved documentation, among others.; - Patient education was designed to empower the patient in self-monitoring and self-care during upsetting event (eg, anger reduction strategies); Persuasion:; - Staff encouraged to develop individualized plans with patients.; - A large story board that had graphs and charts with this information was placed in a prominent location on the unit.; Training:; - Treatment planning teams were trained and encouraged to develop individualized plans for all patients.; - Nursing employees completed a training program that emphasized the ethical aspects of work-related boundaries, successful interaction styles to assist the patient in self-monitoring and utilization of adaptive problem-solving skills.; - The assault program was a developed to give structured individual attention to the patient and focus on the development of nonviolent coping skills. This program included detailed behavioral goals and required a collaborative and educational exchange between a staff member and the patient.; Environment:; - A larger paradigm shift from a culture of control to collaboration. The goal of these changes was to create an environment that fostered the treatment of all persons with respect, dignity, and mutuality.; - A 23-item audit tool was developed that addressed the issues of justification of S/R, assessment, care during and after the procedure, and documentation. The nurse who released the patient from S/R was assigned the audit tool.; - Quarterly reports were compiled that tracked incidents and trends by shift, unit, and patient which were distributed to unit nurses.; - Environmental alterations included the Oasis Room, which was renovated with carpet, comfortable furniture, and reading material. The room was designed to provide patients with a quiet pleasant environment to practice calming techniques.; - Events of S/R was evaluated by the nurse project manager to determine appropriateness of the event, attempts to use less restrictive alternatives prior to the incident, care during the incident, and care immediately after the incident.; Enablement:; - Creating behavioral goals required a collaborative and educational exchange between a staff member and the patient.; - There was a consistent emphasis from the project manager and the management team that the staff maximize collaborative exchanges and de-emphasize control tactics.
| | Pre-intervention (practice as usual) | NA | NA | NA | NA
Whitecross, 2020, Australia, Pre-post | Study researchers | Psychiatric behavior of concern (Psy-BOC) team | No | After experiencing a substantial increase in aggression in 2016, the service sought to examine the causes and design a new response approach. The “Plan, Do, Study, Act” (PDSA) methodology was used to understand the need for, design, and refine a multidisciplinary team-based response (Taylor et al., 2014).^31^ | Implementation of Psy-BOC would reduce restrictive intervention (e.g., seclusions and security involvement) use and harmful behavior occurrence on the unit. | Education:; - Created and distributed “A Behaviors of Concern (Psy-BOC) Call Psychiatry” guideline to educate staff.; Environment:; - A rostered multidisciplinary team was made available during business hours (triage psychiatry or registrar assistance provided after business hours support) with expertise in behavioral management to assist the treatment team in managing behavioral deterioration. Disciplines represented included medical, nursing, psychology, social work, occupational therapy, art and music therapy, and consumer and carer peer support.; - A Psy-BOC call signaled a need for support in responding to an escalating behavior of concern. The call was sent vias SMS to the rostered Psy-BOC team members.; Modeling:; - The Psy-BOC team modelled how to respond during de-escalation to build staff and patient capacity and contributed to behavior management planning.
Whitecross, 2020, Australia, Pre-post | Study researchers | Pre-intervention (practice as usual) | NA | NA | NA | NA
Zuehlke, 2016, United States, Pre-post | Long Beach VA | Recovery-oriented program of care | Yes | The VHA has embraced/endorsed the recovery-oriented care model with prior research showing efficacy of recovery interventions in quality-of-care improvements (U.S. Department of Veterans Affairs, Veterans Health Administration, 2013).^32^ | Recovery-based models of care and the fostering of empowerment and hope may yield more positive patient outcomes. | Training:; - The staff recovery intervention education was an 8-week training designed to be brief, basic, and applicable to everyday nursing on an inpatient unit. Each 20-min session presented a new recovery-oriented skill and included role playing.; Environment:; - Interdisciplinary recovery team meetings occurred weekly and included inpatient leadership, peer specialists, and a rotating group of frontline nursing staff. These meetings allowed for the discussion of recovery-based improvements on the unit.; - Patients gave input to programmatic changes during weekly community meetings.; - Recovery-oriented group programming (psychoeducational, recreational, peer-support, and process therapy groups) were increased during the weekdays and added to the weekends.; - A certified peer specialist was added to the inpatient unit as an integrated team member who met with patients individually for recovery goal development, assisted patients with accessing resources, and led support group.; Enablement:; - Treatment planning process was modified to include more direct patient participation. Patients were provided a worksheet about goals, objectives, strengths, and preferences, which was incorporated into the treatment plan.
Zuehlke, 2016, United States, Pre-post | Long Beach VA | Pre-intervention (practice as usual) | NA | NA | NA | NA
APNA statement, 2018^a^ | American Psychiatric Nurses Association (APNA) | Position Statement on S/R | No | NR | NA | Education:; - Opportunities for professional growth and learning to develop a treatment approach that promotes individual safety, as well as autonomy and a sense of personal control; Persuasion:; - Oversight of S/R as part of an organization’s performance improvement effort with data open for inspection by internal and external regulators; - Advocate for policies at federal, state, and organizational levels that will protect individuals from needless trauma associated with S/R.; - Argue that individuals have the right to be treated with respect and dignity and in a safe, humane, culturally sensitive and developmentally appropriate manner that respects individual choice and maximizes self-determination.; Training:; - Opportunities for professional growth and learning to develop a treatment approach that promotes individual safety, as well as autonomy and a sense of personal control.; - Healthcare organizations must make commitments to assure that staff are adequately trained and currently competent to perform treatment processes, milieu management, de-escalation techniques and S/R.; Restriction:; - S/R must never be used for staff convenience or to punish or coerce individuals.; - S/R must be used for the minimal amount of time necessary and only to ensure the physical safety of the individual or others, and when less restrictive measures have proven ineffective.; Environment:; - Create a work culture that supports minimal S/R use and that will enable the vision of elimination to be realized.; - Support evidence-based practice through research on the variables associated with the prevention and management of behavioral emergencies.; - Effective administrative and clinical structures and processes must be in place to prevent behavioral emergencies and to support the implementation of alternatives.
Ashcraft, 2012^a^ | Recovery Innovations Inc. | No force first (NFF) policy | No | Leadership moved towards a recovery-oriented model following “dismal outcomes produced by the traditional approach to service delivery” | NA | Education:; - Design and implement self-directed education to reduce reliance on “compliance oriented” services such as medication monitoring.; Persuasion:; - Changing the mission statement from one that focused on stabilization to one that embodied a commitment to recovery.; - NFF is stressed during new employee selection and orientation.; - NFF policy defined the use of force and coercion as a treatment failure.; - Critical incidents were tracked and reported with feedback provided to staff and stakeholders.; - The leadership team held open forums for staff members to express their fears associated with elimination of S/R Leadership replaced fears with the recovery values of hope, choice, and empowerment.; - Weekly e-mails presented stories and videos of the downside of using force.; Training:; - Staff training in effective de-escalation techniques and the NFF process.; - Support the training of law enforcement personnel, families, and guardians in the NFF process.; - Staff are trained that the only restrictive intervention allowed in the facility is emergency forced psychotropic medication.; - Debriefing reports are reviewed with quality management personnel as part of the ongoing training.; Restriction:; - President and chief executive officer mandated that S/R practices would no longer be used and that the NFF policy would be implemented companywide.; - Force of any kind is used only as a last resort, even when people may appear to be a danger to themselves or others.; - Use involuntary inpatient treatment only for individuals who present a clear danger to self or others and only after choice-based voluntary alternatives were attempted.; Environment:; - Characterize staff-patient relationships as “risk-sharing” partnerships instead of “risk management” control; - Development of a recovery culture that stresses the importance of helping to develop meaning, purpose, and spirituality in people’s lives; - Over 50% of staff members are peer support specialists, who understand the trauma caused by S/R.
Clement, 2021^a^ | Clement J. Zablocki VA Medical Center | Least restrictive means, documentation & staff training | Yes | To produce a policy that maintains the Medical Center’s alignment with The Joint Commission’s standards related to the use of S/R | NA | Education:; - Education provided on least restrictive interventions that should be considered before initiating restraints (eg, decreasing stimulation).; - Patient and family are educated on behaviors that require the use of S/R and least restrictive alternatives.; - Criteria for discontinuing restraints is communicated to the patient.; Persuasion:; - Staff are expected to be active participants in care planning and to engage in skillful communication with team members to ensure S/R minimization.; - Providers should recognize individual manifestations of fatigue, anxiety, and increasing stress, and intervene as soon as possible.; - Staff should deploy active listening, reality orientation, or affirm disorientation based on the situation and provide family or visitor support.; Training:; - Individuals ordering S/R must have previously completed requirements for education on S/R policy.; - Staff caring for patients in S/R must demonstrate competency on (1) Strategies to identify staff and patient behaviors, events, and environmental factors that may trigger the use of S/R (2) De-escalation techniques (3) Safe use of restraints (4) Application of hospital approved types of restraints (5) Safe use of seclusion.; - Staff who perform and document patient assessments when S/R are used must demonstrate competency in (1) Assessments needed to identify risks for patients and staff related to S/R (2) Identification of alternatives to S/R, requirements for continued monitoring, and assessment and reassessment needs of patients (3) Skills to manage emergency responses related to S/R.; Restriction:; - S/R use is limited to clinically justified situations or when warranted by patient behavior that threatens the physical safety of the patient, staff, or others.; - S/R may not be used for coercion, discipline, convenience, or retaliation and may not be based solely on a patient’s history of dangerous behavior.; - Alternatives should be used or considered prior to S/R.; - If S/R is employed, the least restrictive intervention is used to protect the patient, staff, or others.; - If S/R is initiated or discontinued by a nurse without an initial order, a licensed independent practitioner must be notified within 1 hour and an order must be entered in the electronic health record within 6 hours.; - As needed, PRN orders, or trials of S/R are not acceptable.; - Time limited orders must be entered in the electronic health record and are not to exceed 4 hours.; Environment:; - Decrease stimulation and promote a calm environment, via noise reduction strategies, evaluation of light levels, calming music or TV and aromatherapy. Provide opportunity for physical activity, distraction, or diversional activities; - Promote comfort and evaluate need for adequate pain management. Ensure basic needs are met and sensory aids are in place; - Medical Center Director and Associate Director for Patient Care Services are responsible for ensuring policy compliance.; - Registered Nurses caring for patients are responsible for plus performing and/or supervising patient monitoring, application and removal of S/R and provision of nursing care.; - Restraint and Seclusion committee are responsible for analyzing S/R data to identify opportunities for improvement, recommend action plans to improve S/R processes, and decrease S/R.
Iwamasa, 2017^a^ | VHA Seclusion and Restraint Reduction Workgroup | Seclusion and Restraint Reduction Toolkit | Yes | In 2017, a Seclusion and Restraint Reduction Workgroup convened and used the National Association of State Mental Health Program Directors’ Six Core Strategies Approach to Reduce the Use of Seclusion and Restraint (Huckshorn, 2004,^33^ 2006)^34^ as the framework for developing this toolkit. Also included existing VHA tools and resources that do not necessarily fit neatly into the 6 core strategy categories. | NA | Education:; - Facility leaders complete a self-assessment of current S/R practices and a plan for making the zero S/R vision a practice reality by analyzing other successful organizations.; - Staff education should include debriefing with each patient after each restraint episode.; - Toolkit includes information brochure for patients/families, and a voluntary treatment agreement.; Persuasion:; - Facility plans contain clear expectations, outcomes, and timelines. Facility leadership requests feedback patients and families regarding the use of S/R.; - All strategies are directed at persuading clinicians to reduce S/R with the goal of providing recovery-oriented services.; - Effective debriefing can help to foster the belief that the event was clinically driven event to assist the patient with regaining control vs punitive.; - Self-control strategies should be incorporated within treatment plans using a collaborative approach between staff and Veterans.; Environment:; - Facility leadership ensures the unit environmental design provides opportunities for relaxation and promotes space for therapeutic staff and Veteran interactions.; - Leadership to work towards developing a culture of safety. Facility executives should provide guidance, direction, participation, and ongoing review of processes within the facility as they relate to patient care, the facility’s mission, philosophy of care and guiding values that demonstrate congruence to obtaining a zero S/R environment.; - Use of comfort rooms, meditation, relaxation, and sensory modulation; - Toolkit includes a design guide which emphasizes home-like, non-institutional, and patient-centered environments that imbue healing, familiarity, and a sense of being valued.; - Inpatient staff should collaborate with quality management to access data and run reports used to assess process improvement efforts.; - Implement a regular data review workgroup meeting schedule and review and update existing S/R policies as needed.; - Mental health environment of care checklist focuses on the removal of environmental hazards that could increase the risks of self-harm.; Enablement:; - Input from patients and their families is critical to understanding existing problems and developing approaches which align with mission of reducing S/R.
VA Northern California HCS^a^ | VA Northern California Health Care System: Mather Behavioral Health Inpatient Care Unit | “Code green” response | Yes | NR | NA | Persuasion:; - Any staff member concerned with a patient’s potential for perpetrating a behavioral emergency should notify other staff. Clinical consultation may help to avert an escalation to a behavioral emergency.; - During a code green, the team leader creates a plan which involves verbal intervention (if anyone in the response group as a positive relationship with the patient they should be assigned responsibility for the verbal de-escalation) and show of support/force in which the patient is given the reason for the team response and offered a clear behavioral options.; Training:; - All staff complete training on prevention and management of behavioral emergencies and disruptive behavior. The training course will include information on hospital policies, verbal intervention strategies and physical control techniques.; Restriction:; - Code green is initiated only after appropriate clinical measures and de-escalation strategies have been ineffective.; - If the patient is unable to regain control a “therapeutic containment” is performed using appropriate techniques. Only non-offensive physical interventions are authorized in behavioral emergencies. To prevent injury to staff and the patient, physical restraint should not be attempted with fewer than 3 team members.; Environment:; - Any VA employee observing a behavioral emergency may initiate a code green. If a professional staff member of a mental health program is present, they should assume this responsibility. The procedure is initiated by accessing the overhead paging system, then announcing “code green, (dayroom, group room, north corridor, etc).”; - Upon becoming aware of the code green, available staff, police, and other employees in the vicinity should converge on that location but “stand away” from the patient unless instructed otherwise. All nonessential personnel should be removed (including patients and visitors) as well as all potentially injurious objects.; - Quiet Room is a safe area with enhanced monitoring to escort patients with escalating anxiety or aggression.; - During a code green, the team leader creates a plan which involves task assignment and transfer of responsibility. (The team leader may request another team member take the lead if he/she feels the patient would respond better or if another staff member has more experience.); Enablement:; - A debriefing should follow within 48 hours of the completion of any code green procedure. The purpose of the debriefing is to focus on needed areas of improvement in managing such incidents and to allow staff to ventilate feelings.
Wale, 2011^a^ | New York City Health and Hospitals Corporation (HHC) | Seclusion and Restraint Reduction Initiative | No | In 2007, to continue the culture change from a medical model to a patient-centered rehabilitation and recovery-oriented service system, HHC launched the S/R Reduction Initiative. The goals of the initiative included further reductions in S/R use and continued culture change to make the psychiatric inpatient and emergency services more patient centered and trauma informed. Interdisciplinary change teams that would oversee the initiative at each facility were established. Teams included all disciplines, peer counselors, hospital security staff, and training and quality-improvement personnel. | NA | Education:; - Guideline on the use of sensory modulation tools and techniques was distributed along with a sensory modulation staff training course.; - HHC issued corporate guidelines to assist facilities with the revisions to facility-specific policies and procedures to bring them in line with changes in The Joint Commission and Centers for Medicaid and Medicare Services regulations.; Persuasion:; - HHC contracted with Office of Technical Assistance (OTA) faculty to provide consultation. At each site, the consultants met with the facility’s behavioral health leadership team, quality-improvement staff, nursing leadership, and frontline staff to get a thorough picture of the facility’s efforts to reduce the use of S/R. The consultants reviewed S/R documentation in a random sample of facility records. They then prepared summary reports of their findings, and their analysis of hospital strengths and priority areas recommended for improvement.; Incentivization:; - A competition was announced with a prize for the facility demonstrating the greatest improvement in a year.; Training:; - “Creating Violence Free and Coercion Free Mental Health Treatment Environments for the Reduction of Seclusion and Restraint” training from the OTA included 3 2-day training sessions. Participants were introduced to 6 core strategies that have been proven to reduce S/R use including concepts of primary and secondary prevention, leadership roles and responsibilities, key characteristics of trauma-informed care systems, using data to inform practice, environmental factors that can be modified to create a safer or calmer environment, rigorous post-event debriefing, and consumer and family roles in the inpatient setting.; - Train-the-trainer models for crisis prevention and management were developed including sixteen highly interactive sessions to develop crisis de-escalation skills using a graded system of alternatives.; - HHC hired sensory modulation experts to train staff.; - Training modules for hospital police to clarify their role when asked to respond to a patient who is agitated or in crisis.; Restriction:; - A 2-hour maximum limit on an S/R order for adults; Other:; - HHC facilities were asked to submit S/R data to the corporate office before the project was officially announced so that a baseline could be analyzed. Since the kick-off, facilities have been submitting data on S/R use and patient and staff injuries with monthly data reviews. The data are also shared quarterly in a comprehensive data book with corporate and individual facility S/R trend charts.

Notes.

a Protocol without evaluation study results.

Abbreviations. APNA=American Psychiatric Nurses Association; BPRS=Brief Psychiatric Rating Scale; BVC=Brøset Violence Checklist; CPM=crisis prevention management; CRMI=clinical risk management initiatives; DoD=Department of Defense; HHC=Health and Hospitals Corporation; JCAHO=Joint Commission on Accreditation of Healthcare Organizations; MAAP=Management of Acute Arousal Program; MASS=modified agitation severity scale; NFF=no force first; NYSPI=New York State Psychiatric Institute; OTA=Office of Technical Assistance; PDSA=plan, do, study, act; PRN=pro re nata; SM=sensory modulation; S/R=seclusion and restraint; VA=Veterans Affairs.

4 Bowers L, Flood C, Brennan G, et al. (2006) A trial to reduce conflict and containment on acute psychiatric wards: city nurses. Journal of Psychiatric and Mental Health Nursing 13, 165–172.

5 Brennan G, Flood C, & Bowers L. (2006) Constraints and blocks to change and improvement on acute psychiatric wards – lessons from the City Nurses project. Journal of Psychiatric and Mental Health Nursing 13, 475–482.

6 Flood C, Brennan G, Bowers L, et al. (2006) Reflections on the process of change on acute psychiatric wards during the City Nurses project. Journal of Psychiatric and Mental Health Nursing 13, 260–268.

7 Watson J. (2012). Human caring science: A theory of nursing (2nd ed.). Jones & Bartlett Learning.

8 Champagne T, & Stromberg N. (2004). Sensory approaches in inpatient psychiatric settings. Innovative alternatives to seclusion and restraint. Journal of Psychosocial Nursing, 43(9), 35–44.

9 Azuela G, & Robertson L (2016). The effectiveness of a sensory modulation workshop on health professional learning. The Journal of Mental Health Training, Education and Practice, 11(5), 317-331. doi:10.1108/JMHTEP-08-2015-0037

10 Champagne T. (2008). Sensory modulation & environment: Essential elements of occupation (3rd ed.). Southampton, MA: Champagne Conferences & Consultation.

11 Sutton D, & Nicholson E (2011). Sensory modulation in acute mental health wards: A qualitative study of staff and service users’ perspectives. Auckland, New Zealand: Te Pou o Te Whakaaro Nui.

12 MacDaniel M, Van Bramer J, and Hogan MF. Comfort rooms: a preventative tool to reduce the use of restraint and seclusion in facilities that serve individuals with mental illness (2009). New York, NY: New York State Office of Mental Health; National Executive Training Institute (NETI). Training curriculum for reduction of seclusion and restraint. Draft curriculum manual (2003). Alexandria, VA: National Association of State Mental Health Program Directors, National Technical Assistance Center for State Mental Health Planning; Champagne T and Stromberg N (2004). Sensory approaches in inpatient psychiatric settings: innovative alternatives to seclusion and restraint. Journal of Psychosocial Nursing and Mental Health Services; 42: 1–8.

13 MacDaniel M, Van Bramer J, and Hogan MF. Comfort rooms: a preventative tool to reduce the use of restraint and seclusion in facilities that serve individuals with mental illness (2009). New York, NY: New York State Office of Mental Health

14 MacDaniel M. (2009, February). Comfort rooms: A preventative tool used to reduce the use of restraint and seclusion in facilities that serve individuals with mental illness. Retrieved from the New York Office of Mental Health website: http://www.omh.state.ny.us/omhweb/resources/publications/comfort_room/

15 Alligood MR, & Tomey AM. (2010). Nursing Theorists and Their Works. Maryland Heights: Mosby Elsevier.

16 Almvik R & Woods P. (1999) Predicting inpatient violence using the Brøset Violence Checklist (BVC). International Journal of Psychiatric Nursing Research 4, 498–505.

17 Abderhalden C, Needham I, Dassen T, Halfens R, Haug HJ, Fisher JE. Structured risk assessment and violence in acute psychiatric wards: randomised controlled trial. Br J Psychiatry 2008; 193: 44–50.

18 Almvik R. & Woods P. (1999) Predicting inpatient violence using the Brøset Violence Checklist (BVC). International Journal of Psychiatric Nursing Research 4, 498–505.

19 Almvik R. & Woods P. (1999) Predicting inpatient violence using the Brøset Violence Checklist (BVC). International Journal of Psychiatric Nursing Research 4, 498–505.

20 Strout TD. Development of an agitation rating scale for use with acute presentation behavioral management patients [Doctoral dissertation, Connell School of Nursing]. Boston College. 2011. https://dlib.bc.edu/islandora/object/bc-ir%3A101860/datastream/PDF/download/citation.pdf

21 D’Orio BM, Purselle D, Stevens D, and Garlow SJ (2004). Reduction of episodes of seclusion and restraint in a psychiatric emergency service. Psychiatric Services. 55:581583; Schreiner, G.M., Crafton, C.G. and Sevin, J.A. (2004) Decreasing the use of mechanical restraints and locked seclusion. Administration and Policy in Mental Health. 31: 449463.

22 Bowers L, 2014. Safewards: a new model of conflict and containment on psychiatric wards. J. Psychiatr. Ment. Health Nurs. 21, 499–508.

23 Fiorillo A, De Rosa C, Del Vecchio V, et al. How to improve clinical practice on involuntary hospital admissions of psychiatric patients: suggestions from the EUNOMIA study. Eur Psychiatry. 2011;26(4):201-207. doi:10.1016/j.eurpsy.2010.01.013

24 Coussens A. (2010). Methodisch Werken in De Gezondheidszorg. Garant: Antwerpen & Apeldoorn; Tiemens, B., Kaasenbrood, A. & De Niet, G. (2010). Evidence Based werken in de GGZ. Houten: Bohn Stafleu van Loghum; Winkelaar, P. H. (2001). Methodisch Werken: Inleiding Tot Methodisch Handelen Met En Voor Mensen. Leusden: De Tijdstroom.

25 Andresen R, Caputi P, & Oades LG (2000). Interrater reliability of the Camberwell assessment of need short appraisal schedule. Australian and New Zealand Journal of Psychiatry, 34 (5), 856–861.

26 Bowers L, Alexander J, Bilgin H, et al. (2014). Safewards: the empirical basis of the model and a critical appraisal. Journal of Psychiatric and Mental Health Nursing, 21, 354–364.

27 Huckshorn KA (2004). Reducing seclusion and restraint use in mental health settings: Core strategies for prevention. Journal of Psychosocial Nursing, 42(9), 22–33.

28 Joint Commission on Accreditation of Healthcare Organizations: Comprehensive Accreditation Manual for Hospitals: The Official Handbook. Oakbrook Terrace, Illinois, Joint Commission Resources, 2000.

29 Hem MH, Pedersen R, Norvoll R, Molewijk B. Evaluating clinical ethics support in mental healthcare: a systematic literature review. Nurs Ethics. 2015;22(4):452–66.

30 Molewijk AC, Abma TA, Stolper M, Widdershoven G. Teaching ethics in the clinic The theory and practice of moral case deliberation. J Med Ethics. 2008 Feb;34(2):120–4.

31 Taylor MJ, McNicholas C, Nicolay C, et al. Systematic review of the application of the plan–do–study–act method to improve quality in healthcare. BMJ Qual Saf 2014; 23: 290–298.

32 U.S. Department of Veterans Affairs, Veterans Health Administration. (2013). Handbook 1160.06. Inpatient Mental Health Services Handbook. Retrieved from http://www.va.gov/vhapublications/ViewPublication.asp?pub_ID2937

33 Huckshorn KA (2004; Sept). Reducing the use of seclusion and restraint in mental health systems: A public health prevention approach with interventions. Journal of Psychosocial Nursing and Mental Health Services. (September Special Issue; Guest Editor), 42, 22–33.

34 Huckshorn KA (2006) Re-designing State mental health policy to prevent the use of seclusion and restraint. Administration and Policy in Mental Health, 33, 482–491.