# APPENDIX G BASELINE DATA

Author, Year, PMID, Country, Design | Group Names | N Total Units; N Patients | Race/Ethnicity, % | Age, Mean (SD) or % | Male, % | Clinical Diagnosis, %
Hospital/Unit Restructuring
Hochstrasser, 2018, 29331599, Switzerland, Pre-post | 2015 | 15; 2803 | NR | 46.3 (16.5) | 45.9% | ICD-10; F0 organic, including symptomatic, mental disorders: 4.5%; F1 mental and behavioral disorders due to psychoactive substance use: 22.5%; F2 schizophrenia, schizotypal and delusional disorders: 19.9%; F3 mood (affective) disorders: 28.6%; F4 neurotic, stress-related and somatoform disorders: 15.3%; F6 disorders of adult personality and behavior: 6.6%; Other psychiatric diagnosis: 1.6%; No psychiatric diagnosis: 1.0%
Hochstrasser, 2018, 29331599, Switzerland, Pre-post | 2014 | 15; 2922 | NR | 45.4 (16.5) | 49.7% | ICD-10; F0 organic, including symptomatic, mental disorders: 4.8%; F1 mental and behavioral disorders due to psychoactive substance use: 22.5%; F2 schizophrenia, schizotypal and delusional disorders: 19.2%; F3 mood (affective) disorders: 30.9%; F4 neurotic, stress-related and somatoform disorders: 12.1%; F6 disorders of adult personality and behavior: 8.0%; Other psychiatric diagnosis: 1.5%; No psychiatric diagnosis: 1.0%
Hochstrasser, 2018, 29331599, Switzerland, Pre-post | 2013 | 15; 2989 | NR | 45.8 (16.5) | 47.9% | ICD-10; F0 organic, including symptomatic, mental disorders: 5.9%; F1 mental and behavioral disorders due to psychoactive substance use: 24.4%; F2 schizophrenia, schizotypal and delusional disorders: 17.9%; F3 mood (affective) disorders: 30.4%; F4 neurotic, stress-related and somatoform disorders: 10.9%; F6 disorders of adult personality and behavior: 7.5%; Other psychiatric diagnosis: 1.2%; No psychiatric diagnosis: 1.9%
Hochstrasser, 2018, 29331599, Switzerland, Pre-post | 2012 | 15; 2873 | NR | 45.8 (17.1) | 49.2% | ICD-10; F0 organic, including symptomatic, mental disorders: 5.4%; F1 mental and behavioral disorders due to psychoactive substance use: 23.7%; F2 schizophrenia, schizotypal and delusional disorders: 18.6%; F3 mood (affective) disorders: 30.1%; F4 neurotic, stress-related and somatoform disorders: 10.3%; F6 disorders of adult personality and behavior: 8.2%; Other psychiatric diagnosis: 1.6%; No psychiatric diagnosis: 2.1%
Hochstrasser, 2018, 29331599, Switzerland, Pre-post | 2011 | 15; 2848 | NR | 46.9 (17.6) | 47.1% | ICD-10; F0 organic, including symptomatic, mental disorders: 6.2%; F1 mental and behavioral disorders due to psychoactive substance use: 25.9%; F2 schizophrenia, schizotypal and delusional disorders: 18.2%; F3 mood (affective) disorders: 27.0%; F4 neurotic, stress-related and somatoform disorders: 11.8%; F6 disorders of adult personality and behavior: 7.0%; Other psychiatric diagnosis: 1.8%; No psychiatric diagnosis: 2.1%
Hochstrasser, 2018, 29331599, Switzerland, Pre-post | 2010 | 15; 2924 | NR | 45.9 (16.9) | 47.1% | ICD-10; F0 organic, including symptomatic, mental disorders: 5.1%; F1 mental and behavioral disorders due to psychoactive substance use: 26.7%; F2 schizophrenia, schizotypal and delusional disorders: 20.3%; F3 mood (affective) disorders:27.8%; F4 neurotic, stress-related and somatoform disorders:9.9%; F6 disorders of adult personality and behavior: 6.6%; Other psychiatric diagnosis: 1.6%; No psychiatric diagnosis: 2.1%
Hunter, 1993 8444440, US, Pre-post | After hospital restructuring | 2; 78 | White: 56.1%; Black: 26.7%; Hispanic: 13.9%; American Indian: 0.0%; Other: 2.3% | 44 | 50% | Diagnostic Tool NR; Schizophrenic disorder: 51.4%; Major affective disorder: 20.6%; Organic brain syndrome: 4.1%; Personality disorder: 3.1%; Mental retardation: 1.2%; Other: 19.6%
Hunter, 1993 8444440, US, Pre-post | Before hospital restructuring | 2; 66 | White: 50.1%; Black: 29.6%; Hispanic: 18.1%; American Indian: 0.2%; Other: 1.6% | 44 | 50% | Diagnostic Tool NR; Schizophrenic disorder: 44.4%; Major affective disorder: 22.9%; Organic brain syndrome: 2.0%; Personality disorder: 4.7%; Mental retardation: 0.6%; Other: 25.4%
Rohe, 2017, 26820456 Germany, Pre-post | Architecturally positive redesign | 10; NR | NR | NR | NR | NR
Rohe, 2017, 26820456 Germany, Pre-post | Pre-intervention (practice as usual) | 10; NR | NR | NR | NR | NR
Jenkins, 2014, No PMID, United Kingdom, Pre-post | Purpose-built psychiatric intensive care unit | 1; 18 | NR | 41.6 (12.8) | 100% | ICD-10; F1 mental and behavioral disorders due to psychoactive substance use: 0%; F3 Mood disorders: 6%; F6 Behavior and personality disorders: 0%; F20 Schizophrenia, schizotypal and delusional disorders: 12%; F42 OCD: 0%
Jenkins, 2014, No PMID, United Kingdom, Pre-post | Old unit | 1; 18 | NR | 40.2 (12.7) | 83.4% | ICD-10; F1 mental and behavioral disorders due to psychoactive substance use: 1%; F3 Mood disorders: 3%; F6 Behavior and personality disorders: 1%; F20 Schizophrenia, schizotypal and delusional disorders: 12%; F42 OCD:1%
Staff Education/Training
Bowers, 2008, 18844799, UK, Concurrent | City Nurses intervention – escalation training | 3; NR | NR | NR | NR | NR
Bowers, 2008, 18844799, UK, Concurrent | Concurrent control (practice as usual) | 3; NR | NR | NR | NR | NR
Bowers, 2008, 18844799, UK, Concurrent | Pre-intervention (practice as usual) | 8; NR | NR | NR | NR | NR
Forster, 1999 10565060, United States, Pre-post | Staff training | 4; 3010 | NR | NR | NR | NR
Forster, 1999 10565060, United States, Pre-post | Pre-intervention (practice as usual) | 4; 2560 | NR | NR | NR | NR
Haefner, 2021, 32749904, United States, Pre-post | Post-test | 1; 342 | NR | 18–25: 27.2%; 26–35: 29.5%; 36–45: 24.0%; 46>: 19.3% | 54.1% | Diagnostic Tool NR; Schizophrenia: 31.3%; Schizoaffective disorder: 17.8%; Depression: 9.1%; Bipolar: 25.4%; Psychotic disorder: 16.4%
Haefner, 2021, 32749904, United States, Pre-post | Pre-test | 1; 388 | NR | 18–25: 21.9%; 26–35: 38.4%; 36–45: 19.1%; 46>: 20.1% | 52.3% | Diagnostic Tool NR; Schizophrenia: 30.4%; Schizoaffective disorder: 14.2%; Depression: 10.6%; Bipolar: 25.0%; Psychotic disorder: 19.3%
Sensory Modulation
Lloyd, 2013, No PMID Australia, Concurrent | Sensory modulation room | 1; NR | NR | NR | NR | NR
Lloyd, 2013, No PMID Australia, Concurrent | Concurrent control (practice as usual) | 1; NR | NR | NR | NR | NR
Cummings, 2010, 20349887, United States, Concurrent | Comfort room | 1; NR | NR | NR | NR | NR
Cummings, 2010, 20349887, United States, Concurrent | Concurrent control (practice as usual) | 1; NR | NR | NR | NR | NR
Cummings, 2010, 20349887, United States, Concurrent | Pre-intervention (practice as usual) | 1; NR | NR | NR | NR | NR
Azuela, 2018, No PMID, New Zealand, Pre-post | Sensory modulation room | 2; NR | NR | NR | NR | NR
Azuela, 2018, No PMID, New Zealand, Pre-post | Pre-intervention (practice as usual) | 2; NR | NR | NR | NR | NR
Novak, 2012, 23014117, Australia, Pre-post | Sensory room | 1; NR | NR | NR | NR | NR
Novak, 2012, 23014117, Australia, Pre-post | Pre-intervention (practice as usual) | 1; NR | NR | NR | NR | NR
Novak, 2012, 23014117, Australia, Pre-post | Study | 1; 75^a^ | NR | Under 20: 12.0%; 20–39: 64.7%; 40–59:13.3%; 60 or over: 0.0% | 17.3% | Diagnostic Tool NR; Schizophrenia/other psychoses: 33.3%; Manic episode or bipolar affective disorder: 24.0%; Depression: 8.0%; Borderline personality disorder: 5.3%; Other: 4.0%; Missing: 25.3%
Sivak, 2012, 22439145, United States, Pre-post | Comfort room | 5; NR | White 81.4% | Range 18–79; 50–59: 36.6% | NR | NR
Sivak, 2012, 22439145, United States, Pre-post | Pre-intervention (practice as usual) | 5; NR | NR | NR | NR | NR
Smith, 2013, 24305908, United Kingdom, Pre-post | Sensory room | 1; NR | NR | NR | 100% | NR
Smith, 2013, 24305908, United Kingdom, Pre-post | Pre-intervention (practice as usual) | 1; NR | NR | NR | 100% | NR
Zimmermann, 2020, No PMID, United States, Pre-post | Serenity room | 1; 321 | NR | NR | NR | NR
Zimmermann, 2020, No PMID, United States, Pre-post | Pre-intervention (practice as usual) | NR | NR | NR | NR | NR
Risk Assessment
Abderhalden, 2008, 18700217, Switzerland, RCT | Intervention wards | 4; NR | NR | 39.0 (13.1) | 54.4% | ICD-10; F0 organic, including symptomatic, mental disorders: 3.8%; F1 mental and behavioral disorders due to psychoactive substance use: 26.2%; F2 schizophrenia, schizotypal and delusional disorders: 33.4%; F3 mood (affective) disorders: 15.5%; F4 neurotic, stress-related and somatoform disorders: 14.3%; F6 disorders of adult personality and behavior: 4.0%; Other: 2.7%
Abderhalden, 2008, 18700217, Switzerland, RCT | Waitlist control (practice as usual) | 5; NR | NR | 38.0 (14.3) | 55.2% | ICD-10; F0 organic, including symptomatic, mental disorders: 4.3%; F1 mental and behavioral disorders due to psychoactive substance use: 24.2%; F2 schizophrenia, schizotypal and delusional disorders: 35.7%; F3 mood (affective) disorders: 15.3%; F4 neurotic, stress-related and somatoform disorders: 11.5%; F6 disorders of adult personality and behavior: 5.0%; Other: 4.1%
Abderhalden, 2008, 18700217, Switzerland, RCT | Preference arm (practice as usual) | 5; NR | NR | 41.7 (15.9) | 47.5% | ICD-10; F0 organic, including symptomatic, mental disorders: 1.7%; F1 mental and behavioral disorders due to psychoactive substance use: 27.0%; F2 schizophrenia, schizotypal and delusional disorders: 26.5%; F3 mood (affective) disorders: 21.4%; F4 neurotic, stress-related and somatoform disorders: 21.9%; F6 disorders of adult personality and behavior: NR; Other: 1.4%
Abderhalden, 2008, 18700217, Switzerland, RCT | Study | 14; 2364 | NR | 39.5 (14.2) | 53.4% | ICD-10; F0 organic, including symptomatic, mental disorders: 3.3%; F1 mental and behavioral disorders due to psychoactive substance use: 24.3%; F2 schizophrenia, schizotypal and delusional disorders: 31.0%; F3 mood (affective) disorders: 16.2%; F4 neurotic, stress-related and somatoform disorders: 14.3%; F6 disorders of adult personality and behavior: 3.2%; Other: 2.8%
van de Sande, 2011, 22016437, Netherlands, RCT | Structured risk assessment – intervention period | 2; 207 | Ethic minority: 34% | 38 | 65% | Diagnostic Tool NR; Psychotic disorder: 66.0%; Personality disorder: 28.0%; Drug misuse first diagnosis: 9.0%
van de Sande, 2011, 22016437, Netherlands, RCT | Structured risk assessment - baseline | 2; 80 | Ethic minority: 39% | 38 (13) | 66% | Diagnostic Tool NR; Psychotic disorder: 74.0%; Personality disorder: 25.0%; Drug misuse first diagnosis: 4.0%
van de Sande, 2011, 22016437, Netherlands, RCT | Control (practice as usual) – intervention period | 2; 251 | Ethic minority: 31% | 39.4 | 55% | Diagnostic Tool NR; Psychotic disorder: 49.0%; Personality disorder: 8.0%; Drug misuse first diagnosis: 3.0%
van de Sande, 2011, 22016437, Netherlands, RCT | Control (practice as usual) – baseline | 2; 90 | Ethic minority: 18% | 40 (11) | 60% | Diagnostic Tool NR; Psychotic disorder: 57.0%; Personality disorder: 6.0%; Drug misuse first diagnosis: 3.0%
Blair, 2017, 26897657, United States, Pre-post | Evidence-based principles to reduce seclusion / restraint | 1; 8029 | Black: 16.5%; Spanish/Hispanic: 23.6%; White: 55.3%; Other: 4.6% | > = 12yo: 5.0%; 13–65: 87.2%; > = 66: 7.8% | 51.5% | NR
Blair, 2017, 26897657, United States, Pre-post | Pre-intervention (practice as usual) | 1; 3884 | Black: 15.9%; Spanish/Hispanic: 23.9%; White: 56.3%; Other: 3.9% | > = 12yo: 4.9%; 13–65: 85.9%; > = 66: 9.2% | 50.3% | NR
Clarke, 2010, 20712684, Canada, Pre-post | Brøset Violence Checklist | 1; NR | NR | NR | NR | NR
Clarke, 2010, 20712684, Canada, Pre-post | Pre-intervention (practice as usual) | 1; 48 (pilot trial) | NR | NR | NR | NR
Harrington, 2019, 31206989, Australia, Pre-post | Risk assessment (Clinical Risk Management Initiative) | 1; 965 | NR | Range 18–65 | NR | ICD-10; Schizophrenia, schizoaffective disorder, or psychosis: 51.8%
Harrington, 2019, 31206989, Australia, Pre-post | Pre-intervention (practice as usual) | 1; 1090 | NR | Range 18–65 | NR | ICD-10; Schizophrenia, schizoaffective disorder, or psychosis: 50.5%
Manning, 2022, 36006571, United States, Pre-post | Risk assessment (Modified Agitation Severity Scale) | 1; 389 | NR | NR | NR | NR
Manning, 2022, 36006571, United States, Pre-post | Pre-intervention (practice as usual) | 1; 352 | NR | NR | NR | NR
Manning, 2022, 36006571, United States, Pre-post | Study | 1; 742 | Asian: 0.7%; Black or African American: 11.1%; Indigenous: 8.6%; White: 74.2%; Other: 3.9%; Unknown: 1.5%; Hispanic: 3.8%; Non-Hispanic: 96.2% | 35.76 (12.43) | 50.1% | NR
Trauer, 2010, No PMID, Australia | The Management of Acute Arousal Program | 1; 132 | NR | 36.3 | 62% | ICD-10; Schizophrenia: 32.3%; Psychosis: 8.5%; Schizoaffective: 14.0%; Bipolar:10.4%; (Hypo)mania: 3.7%; Any personality disorder: 23.8%; Borderline pers. disorder: 11.0%; Adjustment disorder: 4.9%; Anxiety disorder: 3.0%; PTSD: 1.8%; Stress:1.2%; Eating disorder: 1.8%; Intentional self harm: 3.7%; Depression: 23.2%; Tobacco: 42.7%; Drug misuse: 30.5%; Alcohol misuse: 18.3%; Suicidal ideation: 10.4%
| Pre-intervention (practice as usual) | 1; 149 | NR | 38.4 | 59% | ICD-10; Schizophrenia: 38.8%; Psychosis: 10.6%; Schizoaffective: 8.5%; Bipolar: 10.1%; (Hypo)mania: 4.3%; Any personality disorder: 18.6%; Borderline pers. disorder: 5.8%; Adjustment disorder: 3.2%; Anxiety disorder: 2.7%; PTSD: 2.7%; Stress: 4.3%; Eating disorder: 0.5%; Intentional self harm: 1.1%; Depression: 14.9%; Tobacco: 31.4%; Drug misuse: 16.0%; Alcohol misuse: 8.5%; Suicidal ideation: 2.1%
Comprehensive/Mixed
Bowers, 2015, 26166187, UK, RCT | Safewards | 16; NR | NR | NR | NR | Diagnoses NR
Bowers, 2015, 26166187, UK, RCT | Control wards (physical health program) | 15; NR | NR | NR | NR | Diagnoses NR
| Intervention wards | 13; 4163 | NR | 41.5 (6.5) | 49% | Diagnoses NR
Välimäki, 2022, 36040740, Finland, RCT | Control wards (practice as usual) | 15; 4186 | NR | 40.0 (5.1) | 56% | Diagnoses NR
Välimäki, 2022, 36040740, Finland, RCT | Study | 27; 8349 | NR | 40.6 (5.7) | 53% | Diagnoses NR
Boumans, 2014, 23890418, Netherlands, Concurrent | Methodological Work Approach | 1; 134 | NR | 39.5 (12.4) | 79.9% | DSM-IV; Emotional disorder: 8.2%; Bipolar disorder: 8.2%; Psychotic disorder: 59.0%; Substance use disorder: 41.8%; Other disorders: 11.2%; Axis 1 unspecified disorders: 11.9%; Personality disorders: 33.6%; Intellectual disabilities: 3.7%
Boumans, 2014, 23890418, Netherlands, Concurrent | Control (practice as usual) | 3; 544 | NR | 38.0 (12.8) | 61.8% | DSM-IV; Emotional disorder: 22.2%; Bipolar disorder: 4.8%; Psychotic disorder: 41.0%; Substance use disorder: 27.8%; Other: 14.3%; Axis 1 unspecified disorders: 19.1%; Personality disorders: 39.2%; Intellectual disabilities: 5.7%
Noorthoorn, 2014, No PMID, Netherlands, Concurrent | Intervention | 1; 768 | NR | 45.6 (14.8) | 43% | DSM-IV Axis 1; Psychosocial problem: 3.0%; Anxiety disorder: 16.0%; Depressive disorder:28.0%; Bipolar I disorder: 7.0%; Psychotic disorder: 17.0%; Dementia and brain disorder: 3.0%; Undetermined: 28.0%; DSM-IV Axis 2; Cluster A personality disorder: 5.4%; Personality disorder NAO:4.0%; Undetermined: 17.0%; No information: 75%
Noorthoorn, 2014, No PMID, Netherlands, Concurrent | Pre-intervention (practice as usual) | 1; 702 | NR | 38.8 (11.7) | 46% | DSM-IV Axis 1; Psychosocial problem: 3.0%; Anxiety disorder: 21.0%; Depressive disorder: 18.0%; Bipolar I disorder: 10.0%; Psychotic disorder: 22.0%; Dementia and brain disorder: 3.0%; Undetermined:24.0%; DSM-IV Axis 2; Cluster A personality disorder:9.3%; Personality disorder NAO: 9.0%; Undetermined: 31.0%; No information: 50.0%
Blair, 2015, 25751828, United States, Pre-post | Engagement Model | NR; NR | NR | NR | NR | NR
Blair, 2015, 25751828, United States, Pre-post | Pre-intervention (practice as usual) | NR; NR | NR | NR | NR | NR
Dickens, 2020, 32691495, Australia, Pre-post | Safewards | 8; NR | NR | NR | NR | NR
Dickens, 2020, 32691495, Australia, Pre-post | Pre-intervention (practice as usual) | 8: NR | NR | NR | NR | NR
Hellerstein, 2007, 17890979, United States, Pre-post | Comprehensive intervention | 3; NR | NR | NR^b^ | 49–67% | NR
Hellerstein, 2007, 17890979, United States, Pre-post | Pre-intervention | NR | NR | NR | NR | NR
Khadivi, 2004, 15534024, United States, Pre-post | Comprehensive intervention | 3;NR | NR | NR | NR | NR
Khadivi, 2004, 15534024, United States, Pre-post | Pre-intervention (practice as usual) | 3;NR | NR | NR | NR | NR
Lewis, 2009, 19291492, United States, Pre-post | Crisis Prevention Management program | 5; NR | NR | NR | NR | NR
Lewis, 2009, 19291492, United States, Pre-post | Pre-intervention (practice as usual) | 5; NR | NR | NR | NR | NR
McDonagh, 2019, No PMID, United States | Recovery-oriented programming | 1; NR | NR | NR | NR | NR
McDonagh, 2019, No PMID, United States | Pre-intervention (practice as usual) | 1; NR | NR | NR | NR | NR
Pollard, 2007, 17102932, United States, Pre-post | Report study-level only | 1; NR | NR | NR | NR | NR
Pollard, 2007, 17102932, United States, Pre-post | Pre-intervention (practice as usual) | 1; NR | NR | NR | NR | NR
Richmond, 1996, 8936879, United States, Pre-post | Comprehensive intervention | 3; NR | NR | NR | NR | NR
Richmond, 1996, 8936879, United States, Pre-post | Pre-intervention (practice as usual) | 3; NR | NR | NR | NR | NR
Stoll, 2022, 35650555, Switzerland, Pre-post | Moral case deliberation | 2; NR | NR | NR | NR | NR
Stoll, 2022, 35650555, Switzerland, Pre-post | Pre-intervention (practice as usual) | 2; NR | NR | NR | NR | NR
Taxis, 2002, 11901660, United States, Pre-post | Comprehensive intervention | 1; NR | NR | NR | NR | NR
Taxis, 2002, 11901660, United States, Pre-post | Pre-intervention (practice as usual) | 1; NR | NR | NR | NR | NR
Whitecross, 2020, 32391731, Australia, Pre-post | Psychiatric behavior of concern team | 1; 89 | NR | 37.3 (9.8) | 62.9% | Diagnostic Tool NR; [underlined: Primary Diagnosis]; Schizophrenia or other psychosis: 68.5%; Affective disorder: 15.7%; Personality disorder or other: 15.7%; [underlined: Secondary Diagnosis]; Alcohol abuse/dependence: 1.1%; Drug abuse/dependence: 51.7%; ID/ABI/Developmental disorder: 4.5%
Whitecross, 2020, 32391731, Australia, Pre-post | Pre-intervention (practice as usual) | 1; 108 | NR | 36.6 (9.7) | 62.0% | Diagnostic Tool NR; [underlined: Primary Diagnosis]; Schizophrenia or other psychosis: 69.4%; Affective disorder: 18.5%; Personality disorder or other: 12.0%; [underlined: Secondary Diagnosis]; Alcohol abuse/dependence: 5.6%; Drug abuse/dependence: 58.3%; ID/ABI/Developmental disorder: 6.5%
Zuehlke, 2016, 27845534, United States, Pre-post | Recovery-oriented program of care | 1; NR | NR | NR | NR | NR
Zuehlke, 2016, 27845534, United States, Pre-post | Pre-intervention (practice as usual) | 1; NR | NR | NR | NR | NR
Zuehlke, 2016, 27845534, United States, Pre-post | Study | 1; 352 | NR | NR | NR | NR

Notes.

a Report sample for patients experiencing a seclusion event, including repeat patients. The unique number of patients was not reported

b 4% of population was aged 13–18.

Abbreviations. ABI=acquired brain injury; ICD-10=International Classification of Diseases 10th Revision; ID=intellectual disability; NR=not reported; S/R=seclusion and restraint.