# APPENDIX F DESIGN DETAILS

Author, Year, PMID, Country | Study Design | Study Dates | Setting | Inclusion Criteria | Exclusion Criteria
Hospital/Unit Restructuring
Hochstrasser, 2018, 29331599, Switzerland | Pre-post | Jan 2010 to Dec 2015 | Single hospital; 15 adult inpatient psychiatric units | Patients ≥18 years of age and admitted to 1 of 15 wards during the study period with capacity for seclusion | NR
Hunter, 1993, 8444440, United States | Pre-post | Mar 1989 to Dec 1990 | Single hospital; 2 22-bed locked adult inpatient psychiatric units | Patients admitted to either unit with capacity for seclusion | NR
Rohe, 2017, 26820456, Germany | Pre-post | Jan 2005 to Dec 2014 | Single hospital; 10 inpatient psychiatric units | Patients admitted to the 10 units with a capacity for seclusion | NR
Jenkins, 2014, No PMID, United Kingdom | Pre-post | Feb 2011 to Feb 2012 | Single hospital; 2 10-bed inpatient psychiatric units (pre-post ward move) | Patients admitted to either unit with capacity for seclusion | NR
Staff Education/Training
Bowers, 2008, 18844799, United Kingdom | Concurrent control | July 2004 to Jan 2006 | Eight acute inpatient psychiatric wards in large metropolitan area | Project advertised to 13 wards, of which 3 applied to participate and were interviewed. Two wards were accepted with an additional ward introduced 9-months into the intervention phase. | NR
Forster, 1999, 10565060, United States | Pre-post | Jan 1995 to Dec 1996 | Single hospital; 4 acute adult inpatient psychiatric units | Patients admitted to the 4 units with a capacity for seclusion | NR
Haefner, 2021, 32749904, United States | Pre-post | Oct 2018 to Feb 2019 | 37-bed adult inpatient psychiatric unit | Patients admitted to the unit with capacity for seclusion | NR
Sensory Modulation
Lloyd, 2013, No PMID, Australia | Concurrent control | Jan to Dec 2011 (Intervention started July 2011) | Single hospital; 2 20-bed acute adult inpatient psychiatric units | Patients admitted to 2 units with capacity for seclusion | NR
Cummings, 2010, 20349887, United States | Concurrent control | NR | Single hospital; 2 acute inpatient psychiatric units | Patients admitted to either unit with capacity for seclusion | NR
Azuela, 2018, No PMID, New Zealand | Pre-post | Sept 2014 to Aug 2016 | Two acute adult inpatient mental health services | Patients admitted to either service with capacity for seclusion | NR
Novak, 2012, 23014117, Australia | Pre-post | NR | Single hospital; 40-bed acute inpatient psychiatric unit | Patients admitted to the unit with capacity for seclusion | NR
Sivak, 2012, 22439145, United States | Pre-post | Jul 2010 to Mar 2011 | Single hospital; 2 adult inpatient psychiatric units | Patients admitted to either unit with capacity for seclusion | NR
Smith, 2013, 24305908, United Kingdom | Pre-post | Sept 2010 to Dec 2012 | Single hospital; 15-bed male inpatient psychiatric intensive care unit | Patients admitted to the unit with capacity for seclusion | NR
Zimmermann, 2020, No PMID, United States | Pre-post | Jan 2019 to Mar 2020 | 16-bed acute adult inpatient psychiatric unit | Patients admitted to the unit with capacity for seclusion | NR
Risk Assessment
Abderhalden, 2008, 18700217, Switzerland | RCT | Jun 2002 to Apr 2004 | Fourteen adult inpatient psychiatric units from 324 across 32 psychiatric hospitals. | Wards where most patients had an acute psychiatric disorder; patients were admitted directly onto the ward; usually discharged in 3 months; 18–65 years old; the ward admitted all potential patients and was not specialized for the treatment of specific disorders. | NR
van de Sande, 2011, 22016437, Netherlands | RCT | NR | Single hospital; 36 beds across 4 adult inpatient psychiatric units | Patients admitted to the 4 units with capacity for seclusion | NR
Blair, 2017, 26897657, United States | Pre-post | Oct 2010 to Sept 2012 | Single hospital; 120-bed adult inpatient psychiatric service | Patients admitted to the psychiatric service with capacity for seclusion | NR
Clarke, 2010, 20712684, Canada | Pre-post | NR | Single hospital; 11-bed psychiatric intensive care unit | Patients admitted to the psychiatric intensive care unit with a capacity for seclusion who provided verbal, documented consent | NR
Harrington, 2019, 31206989, Australia | Pre-post | Oct 2005 to Apr 2009 | Single hospital; 25-bed acute adult inpatient psychiatric unit | Patients admitted to the unit with capacity for seclusion | NR
Manning, 2022, 36006571, United States | Pre-post | NR | Single acute adult inpatient psychiatric unit | Patients admitted to the unit with capacity for seclusion | Patients with a very short length of stay and those deemed inappropriate for the intervention by a clinician (eg., active alcohol withdrawal or similar medication treatments)
Trauer, 2010, No PMID, Australia | Pre-post | Jan 2006 to Jan 2007 | Single hospital; 2 22-bed adult inpatient psychiatric units | Patients admitted to either unit with capacity for seclusion | (Post hoc) all admissions in which the patient had been admitted to the ground floor ward, or had been transferred to or from it, were excluded. Data analysis occurred for only 1 ward, the first floor ward.
Comprehensive/Mixed
Bowers, 2015, 26166187, United Kingdom | RCT | NR | 15 hospitals; 31 acute adult inpatient psychiatric units | Acute psychiatric wards for adults of any gender | Wards with specialist function, who planned major changes, or where ≥2 criteria were met: no permanent ward manager in post, a locum consultant solely responsible for inpatient care, >30% nursing staff vacancy rate
Välimäki, 2022, 36040740, Finland | RCT | Jan 2015 to Dec 2017 | 15 hospitals; 28 inpatient psychiatric units | Wards that are Finnish speaking, have at least 1 psychiatric ward, are open 24/7, and are able to use coercive measures defined in the Finnish Mental Health Act | NR
Boumans, 2014, 23890418, Netherlands | Concurrent | Apr 2008 to Jun 2010 | Single hospital; 4 adult inpatient psychiatric units (21-bed intensive care, 7-bed acute intensive care, 20-bed specialized care, and 18-bed forensic unit) | Patients admitted to the 4 units with a capacity for seclusion | NR
Noorthoorn, 2014, No PMID, Netherlands | Concurrent | Jan 2003 to June 2005 | Two hospitals; 1 45-bed and one 38-bed adult inpatient psychiatric unit | Patients admitted to either unit with capacity for seclusion | NR
Blair, 2015, 25751828, United States | Pre-post | 2000 to 2013 | Single hospital; inpatient psychiatry service | Patients admitted to the psychiatry service with capacity for seclusion | NR
Dickens, 2020, 32691495, Australia | Pre-post | Apr 2019 to Jan 2020 | One health district; 142 beds across eight adult inpatient psychiatric units | All inpatient mental health units within the health district; patients admitted to the 8 units with capacity for seclusion | Units with current or past utilization of Safewards interventions; units non-responsive to research requests
Hellerstein, 2007, 17890979, United States | Pre-post | Sept 2000 to Apr 2006 | Single hospital; 24-bed General Clinical Research Inpatient Unit; 12-bed Schizophrenia Research Unit; 22-bed Washington Heights Community Service Unit | Patients admitted to the 3 units with a capacity for seclusion | NR
Khadivi, 2004, 15534024, United States | Pre-post | 2000 to 2001 | Single hospital; 3 acute adult inpatient psychiatric units | Patients admitted to the 3 units with capacity for seclusion | NR
Lewis, 2009, 19291492, United States | Pre-post | 2004 to 2006 | Single hospital; 88 beds across 5 adult inpatient psychiatric units; 1 general acute unit and four specialty-based service lines | Patients admitted to the 5 units with capacity for seclusion | NR
McDonagh, 2019, No PMID, United States | Pre-post | 2009 to 2018 | Single (VA) hospital; 1 adult inpatient psychiatric unit | Patients admitted to the unit with capacity for seclusion | NR
Pollard, 2007, 17102932, United States | Pre-post | Oct 1998 to Jul 2002 | Single (VA) hospital; 1 acute adult inpatient psychiatric unit | Patients admitted to the unit with capacity for seclusion | NR
Richmond, 1996, 8936879, United States | Pre-post | Feb 1992 to Feb 1993 | Single (VA) hospital; 4 30-bed adult inpatient psychiatric units (three locked and one unlocked) | Patients admitted to the 4 units with capacity for seclusion | NR
Stoll, 2022, 35650555, Switzerland | Pre-post | Jun 2019 to Sept 2020 | Two hospitals; 1 19-bed closed acute geriatric inpatient psychiatric unit and one 19-bed open acute adult inpatient psychiatric unit | Patients admitted to either unit with capacity for seclusion
Taxis, 2002, 11901660, United States | Pre-post | Jun 1996 to Feb 2000 | Single hospital; 86-bed acute adult inpatient psychiatric unit | Patients admitted to the unit with capacity for seclusion | NR
Whitecross, 2020, 32391731, Australia | Pre-post | Aug 2016 to Jul 2017 (Intervention started Feb 2017) | Single hospital; 58-bed adult inpatient psychiatric unit | Patients admitted to the psychiatry service with capacity for seclusion | NR
Zuehlke, 2016, 27845534, United States | Pre-post | Oct 2012 to Sept 2013 | Single (VA) hospital; 15-bed adult inpatient psychiatric unit | Patients admitted to the unit with capacity for seclusion | NR

Abbreviations. NR=not reported; RCT=randomized controlled trial; VA=Veterans Affairs.