# APPENDIX E QUALITY RATINGS FOR ALL ELIGIBLE STUDIES

Author, Year, PMID, Design | Free of Discrepancies | Clarity: Pop | Clarity: Int/Com | Clarity: Outcomes | Clarity: Setting | Missing Results | Outcome Ascertainment | RCT | | Observational Study
Author, Year, PMID, Design | Free of Discrepancies | Clarity: Pop | Clarity: Int/Com | Clarity: Outcomes | Clarity: Setting | Missing Results | Outcome Ascertainment | Adequate Randomization | Adequate Allocation Concealment | Cohort Rep | Comparator Rep | Adjustment for Confounders
Hospital/Unit Restructuring
Hochstrasser, 2018, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | Yes Regression adjustment (Low RoB)
Hunter,1993, 8444440, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^B^ (High RoB)
Jenkins, 2014, No PMID, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Rohe, 2017, 26820456, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Staff Education/Training
Bowers, 2008, 18844799, Concurrent | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Unclear | Yes Regression adjustment (Low RoB)
Forster, 1999, 10565060, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Haefner, 2021, 32749904, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Sensory Modulation
Lloyd, 2013, No PMID, Concurrent | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Unclear | No Crude analysis^b^ (High RoB)
Cummings, 2010, 20349887, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Unclear | No Crude analysis^b^ (High RoB)
Azuela, 2018, No PMID, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Novak, 2012, 23014117, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Sivak, 2012, 22439145, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Smith, 2013, 24305908, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Zimmermann, 2020, No PMID, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Unclear | No Crude analysis^b^ (High RoB)
Risk Assessment
Abderhalden, 2008, 18700217, RCT | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | No (Low RoB) | No (Low RoB) | NA | NA | NA
van de Sande, 2011, 22016437, RCT | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | No (Low RoB) | No (Low RoB) | NA | NA | NA
Blair, 2017, 26897657, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Clarke, 2010, 20712684, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Unclear | Unclear | No Crude analysis^b^ (High RoB)
Harrington, 2019, 31206989, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Unclear | No Crude analysis^b^ (High RoB)
Manning, 2022, 36006571, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Unclear | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Trauer, 2010, No PMID, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | Yes Regression adjustment (Low RoB)
Comprehensive/Mixed
Bowers, 2015, 26166187, RCT | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes^d^ (High RoB) | Self-report^a^ (High RoB) | No (Low RoB) | No (Low RoB) | NA | NA | NA
Valimaki, 2022, 36040740, RCT | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | No (Low RoB) | No (Low RoB) | NA | NA | NA
Boumans, 2014, 23890418, Concurrent | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Noorthoorn, 2014, Concurrent | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB)) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | Yes Regression adjustment (Low RoB)
Blair, 2015, 25751828, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Unclear | Unclear | No Crude analysis^b^ (High RoB)
Dickens, 2020, 32691495, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes^e^ (High RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | Yes Regression adjustment (Moderate RoB)
Hellerstein, 2007, No PMID, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Khadivi, 2004, 15534024, Pre-post | Yes (Low concern) | No (High concern)^c^ | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Lewis, 2009, 19291492, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Unclear | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
McDonagh, 2019, No PMID, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Unclear | Unclear | No Crude analysis^b^ (High RoB
Pollard, 2007, 17102932, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | Yes Regression adjustment (Moderate RoB)
Richmond, 1996, 8936879, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Unclear | No Crude analysis^b^ (High RoB)
Stoll, 2022, 35650555, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Taxis, 2002, 11901660, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Unclear | Unclear | No Crude analysis^b^ (High RoB)
Whitecross, 2020, 32391731, Pre-post | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Yes (Low RoB) | No Crude analysis^b^ (High RoB)
Zuehlke, 2016, 27845534, Pre-post | Yes (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low RoB) | Self-report^a^ (High RoB) | NA | NA | Yes (Low RoB) | Unclear | No Crude analysis^b^ (High RoB)

Notes.

a Self-report of seclusion and/or restraint events of timing of events (including that reported in records)

b Conducted unadjusted analysis

c Unclear sample size, unclear total number of patients or minimal details on patient population

d ≥36% missing data on the patient-staff conflict checklist, which was the primary outcome and a tool completed by a ward nurse at the end of each shift to document patient behavior and ward containment measures

e 36% missing data on the patient-staff conflict checklist, which was the primary outcome and a tool completed by a ward nurse at the end of each shift to document patient behavior and ward containment measures. Intervention was described as being compliant with JCAHO but limited details on core component of the intervention of agitation.

Abbreviations. con=control; int=intervention; pop=population; RCT=randomized controlled trial; rep=representativeness; RoB=risk of bias.