# APPENDIX D STUDIES EXCLUDED AT FULL TEXT

1 Allen DE, de Nesnera A, Souther JW. Executive-level reviews of seclusion and restraint promote interdisciplinary collaboration and innovation. J Am Psychiatr Nurses Assoc 2009;15(4):260–4. 2011 or before.21665812
2 Allerby K, Goulding A, Ali L, T237. Person-centered psychosis care –how increasing person-centeredness in psychosis inpatient care relate to care consumption and ward burden. Schizophrenia Bulletin 2020;46(Supplement_1):S323–S. No outcomes of interest: Abstract results do not report on S/R, just LOS and rating of ward burden.
3 Allikmets S, Marshall C, Murad O, Seclusion: A patient perspective. Issues Ment Health Nurs 2020;41(8):723–35. Qualitative study.32374636
4 Alty A. Nurses' learning experience and expressed opinions regarding seclusion practice within one NHS trust. J Adv Nurs 1997;25(4):786–93. Qualitative study.9104676
5 Andersen C, Kolmos A, Andersen K, Applying sensory modulation to mental health inpatient care to reduce seclusion and restraint: a case control study. Nord J Psychiatry 2017;71(7):525–8. No outcomes of interest (protocol/study registration).28719249
6 Asikainen J, Louheranta O, Vehviläinen-Julkunen K, Use of coercion prevention tools in Finnish psychiatric wards. Arch Psychiatr Nurs 2020;34(5):412–20. Not NA (KQ1).33032767
7 Bar-shalita T. Exploring the effectiveness of a sensory room in reducing seclusion, restraint and aggression at an acute psychiatric unit. 2022. No outcomes of interest (protocol/study registration).
8 Baumgardt J, Jäckel D, Helber-Böhlen H, Preventing and reducing coercive measures- an evaluation of the implementation of the safewards model in two locked wards in Germany. Front Psychiatry 2019;10:340. Not alternative to seclusion (explicit).31178766
9 Baumgardt J, Jäckel D, Helber-Böhlen H, Corrigendum: preventing and reducing coercive measures- an evaluation of the implementation of the safewards model in two locked wards in Germany. Front Psychiatry 2019;10:340. Duplicate.31178766
10 Baumgardt J, Jäckel D, Helber-Böhlen H, Preventing and reducing coercive measures-an evaluation of the implementation of the safewards model in two locked wards in Germany. Front Psychiatry 2020. Duplicate.
11 Baumgardt J, Jäckel D, Helber-Böhlen H, Preventing and reducing coercive measures-an evaluation of the implementation of the safewards model in two locked wards in Germany. Front Psychiatry 2019;10:340. Not alternative to seclusion (explicit).31178766
12 Baumgardt J, Jäckel D, Helber-Böhlen H, Corrigendum: preventing and reducing coercive measures-an evaluation of the implementation of the safewards model in two locked wards in Germany. Front Psychiatry 2020;11:162. Not alternative to seclusion (explicit).32265750
13 Berring L, & Bak J. A new way of handling conflicts. The Nurse 2015;115(13):89–93. Not in English (for KQ1).
14 Bhat S, Rentala S, Nanjegowda RB, Effectiveness of milieu therapy in reducing conflicts and containment rates among schizophrenia patients. Invest Educ Enferm 2020;38(1). Not high-income country (KQ2).
15 Bilgin H, Keser Ozcan N and Boyacioglu NE. Nursing students' opinions on mechanical detecetion method. Turkiye Klinikleri Journal of Nursing Science. 2013;5(2):85–92. Qualitative study.
16 Bille V. Impact of the preventive emotions management questionnaire on the rates of isolation and mechanical restraint measures in the psychiatric admission unit. 2022. ClinicalTrials.gov identifier: NCT05306717. https://www.clinicaltrials.gov/ct2/show/NCT05306717. No outcomes of interest (protocol/study registration).
17 Biondo J. De-escalation with dance/movement therapy: A program evaluation. American Journal of Dance Therapy 2017;39(2):209–25. Not inpatient mental health.
18 Borckardt JJ, Madan A, Grubaugh AL, Danielson CK, Pelic CG, Hardesty SJ, Hanson R, Herbert J, Cooney H, Benson A, Frueh BC. Systematic investigation of initiatives to reduce seclusion and restraint in a state psychiatric hospital. Psychiatr Serv. 2011 May;62(5):477–83. Not inpatient mental health.21532072
19 Boumans CE, Walvoort SJ, Egger JI, The methodical work approach and the reduction in the use of seclusion: how did it work? Psychiatr Q 2015;86(1):1–17. No comparator group (KQ2).25270895
20 Bowers L. Association between staff factors and levels of conflict and containment on acute psychiatric wards in England. Psychiatr Serv 2009;60(2):231–9. Not alternative to seclusion (explicit).19176418
21 Bowers L, Ross J, Nijman H, The scope for replacing seclusion with time out in acute inpatient psychiatry in England. J Adv Nurs 2012;68(4):826–35. No comparator group (KQ2).21749438
22 Bowers L, Van Der Merwe M, Nijman H, The practice of seclusion and time-out on English acute psychiatric wards: the city-128 study. Arch Psychiatr Nurs 2010;24(4):275–86. Not alternative to seclusion (explicit).20650373
23 Bowers L, Wright S, Stewart D. Patients subject to high levels of coercion: staff's understanding. Issues Ment Health Nurs 2014;35(5):364–71. Qualitative study.24766171
24 Buican BJ. The implementation of a psychosocial rehabilitation program at Hawaii state hospital. US: ProQuest Information & Learning; 2001. Forensic population.
25 Canatsey K, Roper JM. Removal from stimuli for crisis intervention: using least restrictive methods to improve the quality of patient care. Issues Ment Health Nurs 1997;18(1):35–44. No comparator group (KQ2).9052099
26 Cano N, Boyer L, Garnier C, [Patients' perception of seclusion in psychiatry: ethical perspectives]. Encephale 2011;37 Suppl 1:S4–10. Qualitative study.21600332
27 Cano N, Boyer L, Garnier C, [Patients' perception of seclusion in psychiatry: ethical perspectives]. Encephale 2011;37 Suppl 1:S4–10. Qualitative study.21600332
28 Carlson JM, Holm MB. Effectiveness of occupational therapy for reducing restraint use in a psychiatric setting. Am J Occup Ther 1993;47(10):885–9. Not alternative to seclusion (explicit).8109608
29 Cashin A. Seclusion: the quest to determine effectiveness. J Psychosoc Nurs Ment Health Serv 1996;34(11):17–21. Not alternative to seclusion (explicit).8923346
30 Veterans Affairs: Ralph H. Johnson VA Medical Center. Position Description (Chaleston, SC). Review or other design not of interest.
31 Chabora N, Judge-Gorny M, Grogan K. The Four S Model in action for de-escalation. An innovative state hospital-university collaborative endeavor. J Psychosoc Nurs Ment Health Serv 2003;41(1):22–8. 2011 or before (for KQ1).
32 Chalmers A, Harrison S, Mollison K, Establishing sensory-based approaches in mental health inpatient care: a multidisciplinary approach. Australas Psychiatry 2012;20(1):35–9. Review or other design not of interest.22357673
33 Chengappa KN, Ebeling T, Kang JS, Clozapine reduces severe self-mutilation and aggression in psychotic patients with borderline personality disorder. J Clin Psychiatry 1999;60(7):477–84. No comparator group (KQ2).10453803
34 Chengappa KN, Levine J, Ulrich R, Impact of risperidone on seclusion and restraint at a state psychiatric hospital. Can J Psychiatry 2000;45(9):827–32. Not alternative to seclusion (explicit).11143833
35 Chengappa KN, Vasile J, Levine J, Clozapine: its impact on aggressive behavior among patients in a state psychiatric hospital. Schizophr Res 2002;53(1–2):1–6. Not alternative to seclusion (explicit).
36 Chieze M, Hurst S, Kaiser S, Effects of seclusion and restraint in adult psychiatry: A systematic review. Front Psychiatry 2019;10:491. Not alternative to seclusion (explicit).31404294
37 Clark LL, Lekkai F, Murphy A, The use of positive behaviour support plans in mental health inpatient care: A mixed methods study. J Psychiatr Ment Health Nurs 2020;27(2):140–50. Not NA (KQ1).31538692
38 Commission J. Specifications Manual for Joint Commission National Quality Measures (v2015B). Not inpatient mental health.
39 Craig JH, Sanders KL. Evaluation of a program model for minimizing restraint and seclusion. Advances in Neurodevelopmental Disorders 2018;2(4):344–52. Pediatric population.
40 Curie CG. SAMHSA's commitment to eliminating the use of seclusion and restraint. Psychiatr Serv 2005;56(9):1139–40. 2011 or before.16148330
41 Currier GW, Farley-Toombs C. Datapoints: use of restraint before and after implementation of the new HCFA rules. Psychiatr Serv 2002;53(2):138. Not alternative to seclusion (explicit).11821540
42 de Cuyper K, Opgenhaffen T, Peeters T, [Flemish guideline for the prevention and use of seclusion and restraint]. Tijdschr Psychiatr 2021;63(4):276–82. Not in English.33913143
43 de Cuyper K, Opgenhaffen T, Peeters T, [Flemish guideline for the prevention and use of seclusion and restraint]. Tijdschr Psychiatr 2021;63(4):276–82. Duplicate.33913143
44 Digby R, Bushell H, Bucknall TK. Implementing a psychiatric behaviours of concern emergency team in an acute inpatient psychiatry unit: staff perspectives. Int J Ment Health Nurs 2020;29(5):888–98. Qualitative study.32243059
45 Dike CC, Lamb-Pagone J, Howe D, Implementing a program to reduce restraint and seclusion utilization in a public-sector hospital: clinical innovations, preliminary findings, and lessons learned. Psychol Serv 2021;18(4):663–70. Forensic population.32940500
46 Doedens P, Vermeulen J, Boyette LL, Influence of nursing staff attitudes and characteristics on the use of coercive measures in acute mental health services-a systematic review. J Psychiatr Ment Health Nurs 2020;27(4):446–59. Qualitative study.31876970
47 Donat DC. Impact of a mandatory behavioral consultation on seclusion/restraint utilization in a psychiatric hospital. J Behav Ther Exp Psychiatry 1998;29(1):13–9. No comparator group (KQ2).9627821
48 Du M, Wang X, Yin S, De-escalation techniques for psychosis-induced aggression or agitation. Cochrane Database Syst Rev 2017;4(4):Cd009922. Not alternative to seclusion (explicit).28368091
49 Duffy RM, Kelly BD. Can the world health organisation's 'quality rights' initiative help reduce coercive practices in psychiatry in Ireland? Ir J Psychol Med 2020:1–4. Not NA (KQ1).
50 Ejneborn Looi GM, Engström Å, Sävenstedt S. A self-destructive care: self-reports of people who experienced coercive measures and their suggestions for alternatives. Issues Ment Health Nurs 2015;36(2):96–103. Qualitative study.25625709
51 Espinosa L, Harris B, Frank J, Milieu improvement in psychiatry using evidence-based practices: the long and winding road of culture change. Arch Psychiatr Nurs 2015;29(4):202–7. SR or CPG.26165973
52 Ezeobele IE, Malecha AT, Mock A, Patients' lived seclusion experience in acute psychiatric hospital in the United States: a qualitative study. J Psychiatr Ment Health Nurs 2014;21(4):303–12. Qualitative study.23834325
53 Finch K, Lawrence D, Williams MO, A systematic review of the effectiveness of safewards: has enthusiasm exceeded evidence? Issues Ment Health Nurs 2022;43(2):119–36. SR or CPG.34534037
54 Finch K, Lawrence D, Williams MO, A systematic review of the effectiveness of safewards: has enthusiasm exceeded evidence? Issues Ment Health Nurs 2022;43(2):119–36. Duplicate.34534037
55 Fletcher J, Hamilton B, Kinner SA, Safewards impact in inpatient mental health units in Victoria, Australia: staff perspectives. Front Psychiatry 2019;10:462. No comparator group (KQ2).31354541
56 Fletcher J, Spittal M, Brophy L, Outcomes of the Victorian safewards trial in 13 wards: impact on seclusion rates and fidelity measurement. Int J Ment Health Nurs 2017;26(5):461–71. No outcomes of interest (mixed population adult and pediatric for outcomes of interest, only report fidelity for adult wards which is not an outcome of interest).28960739
57 Garner B. The evaluation of relaxation massage therapy as an intervention treatment for reducing the level of arousal and aggression on a young adult psychiatric inpatient unit. 2006. ClinicalTrials.gov identifier: NCT00421070. https://www.clinicaltrials.gov/ct2/show/NCT00421070. Pediatric population.
58 Gaskin CJ, McVilly KR, McGillivray JA. Initiatives to reduce the use of seclusion and restraints on people with developmental disabilities: a systematic review and quantitative synthesis. Res Dev Disabil 2013;34(11):3946–61. SR or CPG.24025440
59 Gaynes BN, Brown C, Lux LJ, AHRQ comparative effectiveness reviews. Strategies To De-escalate Aggressive Behavior in Psychiatric Patients. Rockville (MD): Agency for Healthcare Research and Quality (US), 2016. SR or CPG.
60 Gaynes BN, Brown CL, Lux LJ, Preventing and de-escalating aggressive behavior among adult psychiatric patients: a systematic review of the evidence. Psychiatr Serv 2017;68(8):819–31. SR or CPG.28412887
61 Gerle E, Fischer A, Lundh LG. "Voluntarily admitted against my will": patient perspectives on effects of, and alternatives to, coercion in psychiatric care for self-injury. J Patient Exp 2019;6(4):265–70. Qualitative study.31853481
62 Gleerup CS, Østergaard SD, Hjuler RS. Seclusion versus mechanical restraint in psychiatry - a systematic review. Acta Neuropsychiatr 2019;31(5):237–45. SR or CPG.31190673
63 Goldbloom DL, Mojtabai R, Serby MJ. Weekend prescribing practices and subsequent seclusion and restraint in a psychiatric inpatient setting. Psychiatr Serv 2010;61(2):193–5. Review or other design not of interest.20123827
64 Goulet M-H, Larue C, Dumais A. Evaluation of seclusion and restraint reduction programs in mental health: A systematic review. Aggression and Violent Behavior 2017;34:139–46. SR or CPG.
65 Goulet MH, Larue C, Dumais A. From study day to centre for the study of control measures: an example of codevelopment. Int J Ment Health Nurs 2012;21(5):493. Review or other design not of interest.22640233
66 Guivarch J, Cano N. [Use of restraint in psychiatry: feelings of caregivers and ethical perspectives]. Encephale 2013;39(4):237–43. Qualitative study.23747126
67 Haefner J, Dunn I, McFarland M. A quality improvement project using verbal deescalation to reduce seclusion and patient aggression in an inpatient psychiatric unit. Issues Ment Health Nurs. 2021 Feb;42(2):138–144. Duplicate.32749904
68 Haines-Delmont A, Goodall K, Duxbury J, An evaluation of the implementation of a "no force first" informed organisational guide to reduce physical restraint in mental health and learning disability inpatient settings in the UK. Front Psychiatry 2022;13:749615. Forensic population.35185645
69 Hallett N, Dickens GL. De-escalation: A survey of clinical staff in a secure mental health inpatient service. Int J Ment Health Nurs 2015;24(4):324–33. Qualitative study.25975221
70 Hallett N, Dickens GL. De-escalation: A survey of clinical staff in a secure mental health inpatient service. Int J Ment Health Nurs 2015;24(4):324–33. Qualitative study.25975221
71 Hammervold UE, Norvoll R, Sagvaag H. Post-incident reviews after restraints-potential and pitfalls. Patients' experiences and considerations. J Psychiatr Ment Health Nurs 2022;29(3):472–83. Qualitative study.34060178
72 Hammervold UE, Norvoll R, Vevatne K, Post-incident reviews-a gift to the ward or just another procedure? Care providers' experiences and considerations regarding post-incident reviews after restraint in mental health services. A qualitative study. BMC Health Serv Res 2020;20(1):499. Qualitative study.32493391
73 Hammervold UE, Norvoll R, Sagvaag H. Post-incident reviews after restraints-potential and pitfalls. Patients' experiences and considerations. J Psychiatr Ment Health Nurs 2022;29(3):472–83. Qualitative study.34060178
74 Hawsawi T, Power T, Zugai J, Nurses' and consumers' shared experiences of seclusion and restraint: A qualitative literature review. Int J Ment Health Nurs 2020;29(5):831–45. No outcomes of interest: Abstract results do not report on S/R, just LOS and rating of ward burden.32198811
75 Hayashi F, Harsany A, Varvara M, The elimination of seclusion in a geriatric inpatient unit: using environmental modification to effect a cultural change. The American Journal of Geriatric Psychiatry 2015;23(3, Supplement):S122–S3. No outcomes of interest: Abstract results do not report on S/R, just LOS and rating of ward burden.
76 Hernandez A, Riahi S, Stuckey MI, Multidimensional approach to restraint minimization: the journey of a specialized mental health organization. Int J Ment Health Nurs 2017;26(5):482–90. Forensic population.28960744
77 Hernandez A, Riahi S, Stuckey MI, Multidimensional approach to restraint minimization: the journey of a specialized mental health organization. Int J Ment Health Nurs 2017;26(5):482–90. Duplicate.28960744
78 Hirsch S, Steinert T. Measures to avoid coercion in psychiatry and their efficacy. Dtsch Arztebl Int 2019;116(19):336–43. SR or CPG.31288909
79 Hoff AL, Faustman WO, Wieneke M, The effects of clozapine on symptom reduction, neurocognitive function, and clinical management in treatment-refractory state hospital schizophrenic inpatients. Neuropsychopharmacology 1996;15(4):361–9. Not alternative to seclusion (explicit).8887990
80 Huckshorn KA. Reducing seclusion restraint in mental health use settings: core strategies for prevention. J Psychosoc Nurs Ment Health Serv 2004;42(9):22–33. Review or other design not of interest.
81 Huckshorn KA. Re-designing state mental health policy to prevent the use of seclusion and restraint. Adm Policy Ment Health 2006;33(4):482–91. Review or other design not of interest.16244812
82 Huckshorn KA. Reducing seclusion and restraint use in inpatient settings: a phenomenological study of state psychiatric hospital leader and staff experiences. J Psychosoc Nurs Ment Health Serv 2014;52(11):40–7. Qualitative study.25310675
83 Huckshorn KA, LeBel J, Jacobs HE. An organizational approach to reducing and preventing restraint and seclusion use with people with acquired brain injury. NeuroRehabilitation 2014;34(4):671–80. Not inpatient mental health.24796437
84 Huckshorn KA. Reducing seclusion and restraint use in inpatient settings: a phenomenological study of state psychiatric hospital leader and staff experiences. J Psychosoc Nurs Ment Health Serv 2014;52(11):40–7. Duplicate.25310675
85 Huf G, Alexander J, Gandhi P, Haloperidol plus promethazine for psychosis-induced aggression. Cochrane Database Syst Rev 2016;11(11):Cd005146. Not alternative to seclusion (explicit).27885664
86 Huf G, Coutinho ES, Ferreira MA, TREC-SAVE: a randomised trial comparing mechanical restraints with use of seclusion for aggressive or violent seriously mentally ill people: study protocol for a randomised controlled trial. Trials 2011;12:180. Not high-income country (KQ2).21774823
87 Hunter RH, Wilkniss S., Gardner W. I., & Silverstein S. M. The multimodal functional model--advancing case formulation beyond the "diagnose and treat" paradigm: improving outcomes and reducing aggression and the use of control procedures in psychiatric care. Psychological Services 2008;5(1):11–25. 2011 or before.
88 Ifteni P, Szalontay AS, Teodorescu A. Reducing restraint with clozapine in involuntarily admitted patients with schizophrenia. Am J Ther 2017;24(2):e222–e6. Not alternative to seclusion (explicit).27984264
89 Inoue KaT Hisashi and Nakao Kayo and Sayaka Fukui and Fukui Nobuhiko and Sakaguchi Motoaki and Yonashiro Takayuki and Fujiwara Maiko and Kaiya Hisanobu and Okazaki Yuji. A report on research on the use of Risperidone oral solution in a clinical setting. 2006. Not alternative to seclusion (explicit).
90 Janssen W, Noorthoorn E, Linge R, The influence of staffing levels on the use of seclusion. Int J Law Psychiatry 2007;30(2):118–26. Not alternative to seclusion (explicit).17141871
91 Jayaram G, Samuels J, Konrad SS. Prediction and prevention of aggression and seclusion by early screening and comprehensive seclusion documentation. Innov Clin Neurosci 2012;9(7–8):30–8. No comparator group (KQ2).
92 Kalagi J, Otte I, Vollmann J, Requirements for the implementation of open door policies in acute psychiatry from a mental health professionals' and patients' view: a qualitative interview study. BMC Psychiatry 2018;18(1):304. Qualitative study.30231893
93 Kalagi J, Otte I, Vollmann J, Requirements for the implementation of open door policies in acute psychiatry from a mental health professionals' and patients' view: a qualitative interview study. BMC Psychiatry 2018;18(1):304. Qualitative study.30231893
94 Kennedy HG, Mullaney R, McKenna P, A tool to evaluate proportionality and necessity in the use of restrictive practices in forensic mental health settings: the DRILL tool (dundrum restriction, intrusion and liberty ladders). BMC Psychiatry 2020;20(1):515. Forensic population.33097036
95 Kingdon DG, Bakewell EW. Aggressive behaviour: evaluation of a non-seclusion policy of a district psychiatric service. Br J Psychiatry 1988;153:631–4. No comparator group (KQ2).2908238
96 Kirkpatrick H. Inpatients had mostly negative experiences of seclusion during short term treatment in a mental health facility. Evidence Based Mental Health 2000;3(4):128. Qualitative study.
97 Knox DK, Holloman GH Jr. Use and avoidance of seclusion and restraint: consensus statement of the american association for emergency psychiatry project beta seclusion and restraint workgroup. West J Emerg Med 2012;13(1):35–40. Review or other design not of interest.22461919
98 Kontio R, Lahti M, Pitkänen A, Impact of eLearning course on nurses' professional competence in seclusion and restraint practices: a randomized controlled study (ISRCTN32869544). J Psychiatr Ment Health Nurs 2011;18(9):813–21. Not NA (KQ1).21985684
99 Kozub ML, Skidmore R. Least to most restrictive interventions. A continuum for mental health care facilities. J Psychosoc Nurs Ment Health Serv 2001;39(3):32–8. Review or other design not of interest.
100 Krieger E, Fischer R, Moritz S, [Post-seclusion/post-restraint debriefing with patients-overview and current situation]. Nervenarzt 2021;92(1):44–9. Not in English (for KQ1).32725493
101 Kunøe N, Nussle HM, Indregard AM. Protocol for the Lovisenberg Open Acute Door Study (LOADS): a pragmatic randomised controlled trial to compare safety and coercion between open-door policy and usual-care services in acute psychiatric inpatients. BMJ Open 2022;12(2):e058501. Not alternative to seclusion (explicit).
102 Lai CY, Su YY, Lin ST, Music and restraint: emotional control effects on psychiatric patients kept in seclusion. Journal of Nursing and Healthcare Research 2010;6:308–18. Not alternative to seclusion (explicit).
103 Lantta T, Varpula J, Cheung T, Prevention and management of aggressive behaviour in patients at psychiatric hospitals: a document analysis of clinical practice guidelines in Hong Kong. Int J Ment Health Nurs 2020;29(6):1079–91. Qualitative study.32602160
104 Larue C, Dumais A, Drapeau A, Nursing practices recorded in reports of episodes of seclusion. Issues Ment Health Nurs 2010;31(12):785–92. Not alternative to seclusion (explicit).21142599
105 LeBel J. First randomised controlled-trial research on seclusion and restraint reduction achieves intent. Evid Based Ment Health 2014;17(2):40–1. Forensic population.24648332
106 LeBel JL, Duxbury JA, Putkonen A, Multinational experiences in reducing and preventing the use of restraint and seclusion. J Psychosoc Nurs Ment Health Serv 2014;52(11):22–9. Review or other design not of interest.
107 Lee SJ, Cox A, Whitecross F, Sensory assessment and therapy to help reduce seclusion use with service users needing psychiatric intensive care. Journal of Psychiatric Intensive Care 2010;6(2):83–90. No comparator group (KQ2).
108 Ling S, Cleverley K, Perivolaris A. Understanding mental health service user experiences of restraint through debriefing: a qualitative analysis. Can J Psychiatry 2015;60(9):386–92. Qualitative study.26454726
109 Long CG, Afford M, Harris R, Training in de-escalation: an effective alternative to restrictive interventions in a secure service for women. Journal of Psychiatric Intensive Care 2016;12:11–8. Forensic population.
110 Mahlke CI. A randomized controlled trial comparing joint crisis plans with crisis cards for people with bipolar disorders, schizophrenia and other psychotic disorders to reduce involuntary admission and coercive measures. 2017. ClinicalTrials.gov identifier: NCT03240380. https://www.clinicaltrials.gov/ct2/show/NCT03240380. No outcomes of interest.
111 Maier GJ, Van Rybroek GJ, Mays DV. A report on staff injuries and ambulatory restraints: dealing with patient aggression. J Psychosoc Nurs Ment Health Serv 1994;32(11):23–9. Forensic population.
112 Mangaoil RA, Cleverley K, Peter E. Immediate staff debriefing following seclusion or restraint use in inpatient mental health settings: A scoping review. Clin Nurs Res 2020;29(7):479–95. Review or other design not of interest.30051734
113 Mann-Poll PS, Noorthoorn EO, Smit A, Three pathways of seclusion reduction programs to sustainability: ten years follow up in psychiatry. Psychiatr Q 2020;91(3):819–34. Not NA (KQ1).32279142
114 Manzano-Bort Y, Mir-Abellán R, Via-Clavero G, Experience of mental health nurses regarding mechanical restraint in patients with psychomotor agitation: A qualitative study. J Clin Nurs 2022;31(15–16):2142–53. Qualitative study.34459048
115 Manzano-Bort Y, Mir-Abellán R, Via-Clavero G, Experience of mental health nurses regarding mechanical restraint in patients with psychomotor agitation: A qualitative study. J Clin Nurs 2022;31(15–16):2142–53. Qualitative study.34459048
116 Mayers P, Keet N, Winkler G, Mental health service users' perceptions and experiences of sedation, seclusion and restraint. Int J Soc Psychiatry 2010;56(1):60–73. Qualitative study.20053723
117 McKeown M, Thomson G, Scholes A, "Catching your tail and firefighting": the impact of staffing levels on restraint minimization efforts. J Psychiatr Ment Health Nurs 2019;26(5–6):131–41. Qualitative study.31111648
118 Moran A, Cocoman A, Scott PA, Restraint and seclusion: a distressing treatment option? J Psychiatr Ment Health Nurs 2009;16(7):599–605. Qualitative study.19689553
119 Morrison P, Lehane M. Staffing levels and seclusion use. J Adv Nurs 1995;22(6):1193–202. Review or other design not of interest.8675875
120 Muir-Cochrane EC, Baird J, McCann TV. Nurses' experiences of restraint and seclusion use in short-stay acute old age psychiatry inpatient units: a qualitative study. J Psychiatr Ment Health Nurs 2015;22(2):109–15. Qualitative study.25524501
121 Muir-Cochrane EC, Baird J, McCann TV. Nurses' experiences of restraint and seclusion use in short-stay acute old age psychiatry inpatient units: a qualitative study. J Psychiatr Ment Health Nurs 2015;22(2):109–15. Qualitative study.25524501
122 Mullen A, Browne G, Hamilton B, Safewards: an integrative review of the literature within inpatient and forensic mental health units. Int J Ment Health Nurs 2022;31(5):1090–108. SR or CPG.35365947
123 Nagayama Y, Hasegawa M. Nursing care process for releasing psychiatric inpatients from long-term seclusion in Japan: modified grounded theory approach. Nurs Health Sci 2014;16(3):284–90. Qualitative study.25279453
124 Newton-Howes G. Use of seclusion for managing behavioural disturbance in patients. Advances in Psychiatric Treatment 2013;19:422–8. Not alternative to seclusion (explicit).
125 Nocete Navarro L, López de Loma Osorio V, Bravo Ortiz MF, [Mental health and human rights: the experience of professionals in training with the use of mechanical restraints in Madrid, Spain]. Salud Colect 2021;17:e3045. Qualitative study.33822542
126 Noorthoorn EO, Voskes Y, Janssen WA, Seclusion reduction in Dutch mental health care: did hospitals meet goals? Psychiatr Serv 2016;67(12):1321–7. Not alternative to seclusion (explicit).27364814
127 Oberleitner LL. Aversiveness of traditional psychiatric patient restriction. Arch Psychiatr Nurs 2000;14(2):93–7. Review or other design not of interest.10783527
128 Oostermeijer S, Brasier C, Harvey C, Design features that reduce the use of seclusion and restraint in mental health facilities: a rapid systematic review. BMJ Open 2021;11(7):e046647. SR or CPG.
129 Palazzolo J. [About the use of seclusion in psychiatry: the patients' point of view]. Encephale 2004;30(3):276–84. Qualitative study.15235526
130 Palazzolo J, Favre P, Halim V, [Apropos of using patient isolation in psychiatry: point of view of nurses]. Encephale 2000;26(6):84–92. Qualitative study.11217542
131 Papadopoulos C, Bowers L, Quirk A, Events preceding changes in conflict and containment rates on acute psychiatric wards. Psychiatr Serv 2012;63(1):40–7. Qualitative study.22227758
132 Petti TA, Mohr WK, Somers JW, Perceptions of seclusion and restraint by patients and staff in an intermediate-term care facility. J Child Adolesc Psychiatr Nurs 2001;14(3):115–27. Qualitative study.11814078
133 Putkonen A, Kuivalainen S, Louheranta O, Cluster-randomized controlled trial of reducing seclusion and restraint in secured care of men with schizophrenia. Psychiatr Serv 2013;64(9):850–5. Forensic population.23771480
134 Quenum Y. Impact of joint crisis plan on the duration of isolation measures in psychiatry. 2019. ClinicalTrials.gov identifier: NCT03984682. https://www.clinicaltrials.gov/ct2/show/ NCT03984682. Other; no outcomes of interest.
135 Randazzo S. Reserpine in psychotic patients. Full text unavailable.
136 Raveesh BN, Gowda GS, Gowda M. Alternatives to use of restraint: A path toward humanistic care. Indian J Psychiatry 2019;61(Suppl 4):S693–s7. Not alternative to seclusion (explicit).31040459
137 Rixe DBaJ. Use of joint crisis plans for psychiatric patients suffering from psychotic disorders in the context of integrated treatment planning to reduce coercive and measures. German Clinical Trials Register. Pediatric population.
138 Rugkasa J. Reducing Coercion in Norway (RECON). 2019. No outcomes of interest (protocol/study registration).
139 Ryan CJ, Bowers L. Coercive manoeuvres in a psychiatric intensive care unit. J Psychiatr Ment Health Nurs 2005;12(6):695–702. Not alternative to seclusion (explicit).16336594
140 Ryan R, Happell B. Learning from experience: using action research to discover consumer needs in post-seclusion debriefing. Int J Ment Health Nurs 2009;18(2):100–7. Qualitative study.19290973
141 Sailas E, Fenton M. Seclusion and restraint for people with serious mental illnesses. Cochrane Database Syst Rev 2000;2000(2):Cd001163. SR or CPG.10796606
142 Sambrano R, Cox L. 'I sang Amazing Grace for about 3 hours that day': understanding indigenous Australians' experience of seclusion. Int J Ment Health Nurs 2013;22(6):522–31. Qualitative study.23419020
143 Shields M. Holding inpatient psychiatry accountable. ProQuest LLC, 2020. Not alternative to seclusion (explicit).
144 Short R, Sherman ME, Raia J, Safety guidelines for injury-free management of psychiatric inpatients in precrisis and crisis situations. Psychiatr Serv 2008;59(12):1376–8. 2011 or before.19033162
145 Sivakumaran H, George K, Pfukwa K. Reducing restraint and seclusion in an acute aged person's mental health unit. Australas Psychiatry 2011;19(6):498–501. No comparator group (KQ2).22011225
146 Smidth M LB L. Implementing de-escalation in emergency units in psychiatric and general hospitals in Slagelse – a pilot study. International Journal of Integrated Care 2019;19(4):243. Not inpatient mental health.
147 Smith GM, Ashbridge DM, Davis RH, Correlation between reduction of seclusion and restraint and assaults by patients in Pennsylvania's state hospitals. Psychiatr Serv 2015;66(3):303–9. Not alternative to seclusion (explicit).25727119
148 Smith GM, Davis RH, Bixler EO, Pennsylvania State Hospital system's seclusion and restraint reduction program. Psychiatr Serv 2005;56(9):1115–22. 2011 or before.16148327
149 Starkman H. Medical monitoring for agitated patients pilot RCT - medical monitoring. 2015. ClinicalTrials.gov identifier: NCT02512705. https://www.clinicaltrials.gov/ct2/show/ NCT02512705. No comparator group (KQ2).
150 Steinert T. [Benchmarking of freedom-restricting coercive measures in psychiatric hospitals]. Z Evid Fortbild Qual Gesundhwes 2011;105(5):360–4. No outcomes of interest.21767794
151 Steinert T, Bechdolf A, Mahler L, Implementation of guidelines on prevention of coercion and violence (PreVCo) in psychiatry: study protocol of a randomized controlled trial (RCT). Front Psychiatry 2020;11:579176. No outcomes of interest.33101091
152 Steinert T, Fischer-Erlewein E, Kuster W, Prävention von Gewalt im psychiatrischen Krankenhaus: Erste Ergebnisse einer multizentrischen Arbeitsgemeinschaft aus Baden-Württemberg und Bayern. Krankenhauspsychiatrie 2002;13:132–7. No outcomes of interest.
153 Steinert T, Zinkler M, Elsässer-Gaißmaier HP, [Long-term tendencies in the use of seclusion and restraint in five psychiatric hospitals in Germany]. Psychiatr Prax 2015;42(7):377–83. Not alternative to seclusion (explicit).25068687
154 Steinert T, Zinkler M, Elsässer-Gaißmaier HP, [Long-term tendencies in the use of seclusion and restraint in five psychiatric hospitals in Germany]. Psychiatr Prax 2015;42(7):377–83. Not alternative to seclusion (explicit).25068687
155 Sullivan AM, Bezmen J, Barron CT, Reducing restraints: alternatives to restraints on an inpatient psychiatric service--utilizing safe and effective methods to evaluate and treat the violent patient. Psychiatr Q 2005;76(1):51–65. 2011 or before.15757236
156 Sutton D, Wilson M, Van Kessel K, Optimizing arousal to manage aggression: a pilot study of sensory modulation. Int J Ment Health Nurs 2013;22(6):500–11. Qualitative study.23374543
157 Swanson JW, Swartz MS, Elbogen EB, Psychiatric advance directives and reduction of coercive crisis interventions. J Ment Health 2008;17(3):255–67. Not inpatient mental health.20221301
158 Teitelbaum A, Volpo S, Paran R, [Multisensory environmental intervention (snoezelen) as a preventive alternative to seclusion and restraint in closed psychiatric wards]. Harefuah 2007;146(1):11–4, 79–80. Full text unavailable.17294840
159 Tekkaş K, Bilgin H. [Professional containment methods used in psychiatry wards: justifications for their utilization, types, international practices, and perceptions]. Turk Psikiyatri Derg 2010;21(3):235–42. SR or CPG.20818511
160 Terpstra TL, Terpstra TL, Pettee EJ, Nursing staff's attitudes toward seclusion & restraint. J Psychosoc Nurs Ment Health Serv 2001;39(5):20–8. Qualitative study.11360868
161 U.S. Department of Health and Human Services SAMHSA. Promoting alternatives to the use of seclusion and restraint: A national strategy to prevent seclusion issue brief and restraint in behavioral health services. 2010. Not alternative to seclusion (explicit).
162 Välimäki M. The effectiveness of user-driven intervention to manage patient aggression in mental health services. 2016. Duplicate.
163 van Melle AL, Gerritsen S, Zomer LJC, [High and intensive care as a next step in the reduction of coercion]. Tijdschr Psychiatr 2021;63(5):351–7. Not alternative to seclusion (explicit).34043224
164 Van Rybroek GJ, Kuhlman TL, Maier GJ, Preventive aggression devices (PADS): ambulatory restraints as an alternative to seclusion. J Clin Psychiatry 1987;48(10):401–5. 2011 or before.3667538
165 VanDerNagel JE, Tuts KP, Hoekstra T, Seclusion: the perspective of nurses. Int J Law Psychiatry 2009;32(6):408–12. Qualitative study.19837459
166 Varpula J, Välimäki M, Lantta T, Safety hazards in patient seclusion events in psychiatric care: A video observation study. J Psychiatr Ment Health Nurs 2022;29(2):359–73. Qualitative study.34536315
167 Verlinde AA, Snelleman W, van den Berg H, [Involuntary medication as the intervention of choice: can this be regarded as 'substitution' or as a preventive measure? a prospective cohort study]. Tijdschr Psychiatr 2014;56(10):640–8. Not alternative to seclusion (explicit).25327344
168 Visalli H, McNasser G, Johnstone L, Reducing high-risk interventions for managing aggression in psychiatric settings. J Nurs Care Qual 1997;11(3):54–61. No comparator group (KQ2).9029854
169 Voskes Y, van Melle AL, Widdershoven GAM, High and intensive care in psychiatry: A new model for acute inpatient care. Psychiatr Serv 2021;72(4):475–7. Not NA (KQ1).33430651
170 Wharewera-Mika JP, Cooper EP, Wiki NR, Strategies to reduce the use of seclusion with tāngata whai i te ora (Māori mental health service users). Int J Ment Health Nurs 2016;25(3):258–65. Qualitative study.27219838
171 Whittington R, Baskind E, Paterson B. Coercive measures in the management of imminent violence: restraint, seclusion and enhanced observation. In: Richter D, Whittington R, eds. Violence in Mental Health Settings: Causes, Consequences, Management. New York, NY: Springer New York, 2006:145–72. SR or CPG.
172 Yakov S, Birur B, Bearden MF, Sensory reduction on the general milieu of a high-acuity inpatient psychiatric unit to prevent use of physical restraints: A successful open quality improvement trial. J Am Psychiatr Nurses Assoc 2018;24(2):133–44. Not alternative to seclusion (explicit).29039238
173 Ye J, Xiao A, Wang C, Evaluating the effectiveness of a CRSCE-based deescalation training program among psychiatric nurses: a study protocol for a cluster randomized controlled trial. BMC Health Serv Res 2020;20(1):642. Not high-income country (KQ2).32650760