# APPENDIX C CRITERIA USED IN QUALITY ASSESSMENT

Question | Yes | No | Unclear
1. Design; - a. Randomized control trial; - b. Nonrandomized comparison of interventions
2. Was the article free of discrepancies (eg., between text and tables)? Add note if no (high concern)
3. Were patient eligibility criteria sufficiently clear? Add note if no (high concern)
4. Was the alternative seclusion protocol (and comparator) sufficiently clear? Add note if no (high concern)
5. Were outcomes adequately defined without problem? Add note if no (high concern)
6. Was the setting sufficiently clearly defined? (Add note if no (high concern)
7. Were there missing results data for ANY outcomes that occurred in inpatient setting? Were there missing results data for >20% of patients (or imbalance between study groups) for outcomes that occurred after discharge? Add note if yes
8. Outcome assessment; - a. No (or inadequate) description of how seclusion and/or restraint (episodes or timing) was measured (unclear RoB); - b. Independent or blind determination of seclusion and/or restraint (episodes or timing) (low RoB); - c. Self-report (by staff) of seclusion and/or restraint (including that reported in records) (episodes or timing) (high RoB)
9. If RCT, was there inadequate randomization method? Whether randomization was done at the level of the clinic/provider/or the patient, answer no (low RoB) unless there’s an obvious flaw.
10. If RCT, was there inadequate allocation concealment? Whether the randomization was done at the level of the clinic/provider/or patient, answer no unless there’s an obvious flaw. If yes, add a note.
11. If RCT, were staff blinded? Add note if no (high RoB)
12. If observational study, eligible patients receiving care informed by alternative seclusion protocols were all selected or a random selection of patients was used (ie, no concerns about biased selection of alternative seclusion protocol patients). Add note if no (high RoB)
13. If observational study, comparator group (or clinic/ward) was sufficiently similar (and selected patients were all included or a random sample were included). Add note if no (high RoB)
14. If observational study, adjustment for confounders; - a. Crude analysis (unadjusted comparison between alternative seclusion protocol and standard seclusion protocol) (high RoB); - b. Regression adjustment or patient matching (accounting for at least age, sex, and mental health diagnosis) (low RoB); - c. Regression adjustment or patient matching (not accounting for at least 1 one of age, sex, and mental health diagnosis) (moderate RoB); - d. Propensity score analysis (or equivalent) (low RoB)

Abbreviations. RoB=risk of bias.