# APPENDIX B INTERVENTION FUNCTIONS

Intervention Function^a^ | Definition
Education | Increasing knowledge or understanding
Persuasion | Using communication to induce positive or negative feelings or stimulate action
Incentivization | Creating expectation of reward
Coercion | Creating expectation of punishment or cost
Training | Imparting skills
Restriction | Using rules to reduce the opportunity to engage in the target behavior (or to increase the target behavior by reducing the opportunity to engage in competing behaviors)
Environmental restructuring | Changing the physical or social context
Modelling | Providing an example for people to aspire to or imitate
Enablement | Increasing means/reducing barriers to increase capability or opportunity^b^

Notes.

a Intervention functions taken from Michie, S., van Stralen, M.M. & West, R. The behaviour change wheel: A new method for characterising and designing behaviour change interventions. Implementation Sci 6, 42 (2011). https://doi.org/10.1186/1748-5908-6-42. This is an Open Access article distributed under the terms of the Creative Commons Attribution License (http://creativecommons.org/licenses/by/2.0), which permits unrestricted use, distribution, and reproduction in any medium, provided the original work is properly cited.

b Capability beyond education and training; opportunity beyond environmental restructuring.