# APPENDIX A SEARCH STRATEGIES

## PUBMED

("Mental Disorders"[Mesh] OR "Psychiatry"[Mesh] OR "Hospitals, Psychiatric"[Mesh] OR "Mental Health"[Mesh] OR mental[tiab] OR mentally[tiab] OR psychiatr*[tiab] OR schizophren*[tiab] OR psychoti*[tiab]) AND ("Coercion"[Mesh] OR "Patient Isolation"[Mesh] OR "Commitment of Mentally Ill"[Mesh] OR Coerci*[tiab] OR Seclusion[tiab] OR Patient Isolation[tiab] OR Patient Immobili*[tiab] OR Compulsor*[tiab] OR Mentally Ill Commitment*[tiab] OR Involuntary Commitment*[tiab] OR (involunta*[tiab] NOT movement*[tiab]) OR ((lock[tiab] OR locked[tiab] OR locking[tiab] OR contained[tiab] OR containment*[tiab]) AND (door[tiab] OR doors[tiab] OR ward[tiab] OR wards[tiab] OR room[tiab] OR rooms[tiab]))) AND (Prevent* OR avoid* OR deter* OR delay*)

## EMBASE

## COCHRANE

([mh "Mental Disorders"] OR [mh Psychiatry] OR [mh "Hospitals, Psychiatric"] OR [mh "Mental Health"] OR mental:ti,ab OR mentally:ti,ab OR psychiatr*:ti,ab OR schizophren*:ti,ab OR psychoti*:ti,ab) AND ([mh Coercion] OR [mh "Patient Isolation"] OR [mh "Commitment of Mentally Ill"] OR Coerci*:ti,ab OR Seclusion:ti,ab OR "Patient Isolation":ti,ab OR ("Patient" NEXT Immobili*):ti,ab OR Compulsor*:ti,ab OR ("Mentally Ill" NEXT Commitment*):ti,ab OR ("Involuntary" NEXT Commitment*):ti,ab OR (involunta*:ti,ab NOT movement*:ti,ab) OR ((lock:ti,ab OR locked:ti,ab OR locking:ti,ab OR contained:ti,ab OR containment*:ti,ab) AND (door:ti,ab OR doors:ti,ab OR ward:ti,ab OR wards:ti,ab OR room:ti,ab OR rooms:ti,ab))) AND (Prevent* OR avoid* OR deter* OR delay* )

## PSYCINFO

((MH "Mental Disorders"+) OR (MH Psychiatry+) OR (MH "Hospitals, Psychiatric"+) OR (MH "Mental Health"+) OR (TI mental OR AB mental) OR (TI mentally OR AB mentally) OR (TI psychiatr* OR AB psychiatr*) OR (TI schizophren* OR AB schizophren*) OR (TI psychoti* OR AB psychoti*)) AND ((MH Coercion+) OR (MH "Patient Isolation"+) OR (MH "Commitment of Mentally Ill"+) OR (TI Coerci* OR AB Coerci*) OR (TI Seclusion OR AB Seclusion) OR (TI "Patient Isolation" OR AB "Patient Isolation") OR (TI "Patient Immobili*" OR AB "Patient Immobili*") OR (TI Compulsor* OR AB Compulsor*) OR (TI "Mentally Ill Commitment*" OR AB "Mentally Ill Commitment*") OR (TI "Involuntary Commitment*" OR AB "Involuntary Commitment*") OR ((TI involunta* OR AB involunta*) NOT (TI movement* OR AB movement*)) OR (((TI lock OR AB lock) OR (TI locked OR AB locked) OR (TI locking OR AB locking) OR (TI contained OR AB contained) OR (TI containment* OR AB containment*)) AND ((TI door OR AB door) OR (TI doors OR AB doors) OR (TI ward OR AB ward) OR (TI wards OR AB wards) OR (TI room OR AB room) OR (TI rooms OR AB rooms)))) AND (Prevent* OR avoid* OR deter* OR delay* )

## CINAHL

((MH "Mental Disorders"+) OR (MH Psychiatry+) OR (MH "Hospitals, Psychiatric"+) OR (MH "Mental Health"+) OR (TI mental OR AB mental) OR (TI mentally OR AB mentally) OR (TI psychiatr* OR AB psychiatr*) OR (TI schizophren* OR AB schizophren*) OR (TI psychoti* OR AB psychoti*)) AND ((MH Coercion+) OR (MH "Patient Isolation"+) OR (MH "Commitment of Mentally Ill"+) OR (TI Coerci* OR AB Coerci*) OR (TI Seclusion OR AB Seclusion) OR (TI "Patient Isolation" OR AB "Patient Isolation") OR (TI "Patient Immobili*" OR AB "Patient Immobili*") OR (TI Compulsor* OR AB Compulsor*) OR (TI "Mentally Ill Commitment*" OR AB "Mentally Ill Commitment*") OR (TI "Involuntary Commitment*" OR AB "Involuntary Commitment*") OR ((TI involunta* OR AB involunta*) NOT (TI movement* OR AB movement*)) OR (((TI lock OR AB lock) OR (TI locked OR AB locked) OR (TI locking OR AB locking) OR (TI contained OR AB contained) OR (TI containment* OR AB containment*)) AND ((TI door OR AB door) OR (TI doors OR AB doors) OR (TI ward OR AB ward) OR (TI wards OR AB wards) OR (TI room OR AB room) OR (TI rooms OR AB rooms)))) AND (Prevent* OR avoid* OR deter* OR delay* )

## CAIRN.INFO

(Mental Disorders OR Psychiatry OR Psychiatric Hospitals OR Mental Health OR mental OR mentally OR psychiatr* OR schizophren* OR psychoti*)

AND (Coercion OR Patient Isolation OR Commitment of Mentally Ill OR Coerci* OR Seclusion OR Patient Isolation OR Patient Immobili* OR Compulsor* OR Mentally Ill Commitment* OR Involuntary Commitment* OR ((lock OR locked OR locking OR contained OR containment*) AND (door OR doors OR ward OR wards OR room OR rooms)))

AND (Prevent* OR avoid* OR deter* OR delay*)

## CLINICALTRIALS.GOV

(Coercion OR Patient Isolation OR Commitment of Mentally Ill OR Coerci* OR Seclusion OR Patient Isolation OR Patient Immobili* OR Compulsor* OR Mentally Ill Commitment* OR Involuntary Commitment*) AND (Mental Disorders OR Psychiatry OR Psychiatric Hospitals OR Mental Health OR mental OR mentally OR psychiatr* OR schizophren* OR psychoti*)

## PROTOCOLS

The nominating partner made a request for protocols of alternative strategies to seclusion during a monthly VA National Psychiatry Chiefs call on August 12, 2022. Experts attending the call were encouraged to submit existing (and proposed) protocols or policies to reduce seclusion practices for adult patients in inpatient mental health units to the Providence EPC.