# ABBREVIATIONS TABLE

aOR: Adjusted odds ratio
BCW: Behavior change wheel
Cl: Confidence interval
ESP: Evidence Synthesis Program
EssenCES: Essen Client Evaluation Schema
GRADE: Grading of Recommendations Assessment, Development and Evaluation
HR: Hazard ratio
KQ: Key questions
HBIPS: Hospital-based inpatient psychiatric services
MeSH: Medical subject headings
N: Sample size
NR: Not reported
NS: Not significant
NRCS: Nonrandomized comparative study
OMHSP: Office of Mental Health and Suicide Prevention
PCC: Patient-staff conflict checklist
PCC-SR: Patient-staff conflict checklist shift reports
RCT: Randomized controlled trial
RoB: Risk of bias
RR: Relative risk
SD: Standard deviation
TEP: Technical expert panel
US: United States
VA: Veterans Affairs
VHA: Veterans Health Administration