# REFERENCES

1 Vickers A, Zollman C. Massage therapies. BMJ. 1999;319(7219):1254–7.10550095
2 Department of Veterans Affairs. VA HANDBOOK 5005/108 Transmittal Sheet. 2019.
3 NCCIH. Massage Therapy: What You Need To Know. National Institutes of Health. https://www.nccih.nih.gov/health/massage-therapy-what-you-need-to-know
4 Fritz S. Mosby’s fundamentals of therapeutic massage. 2000.
5 Tarver HM, Luchau, T., & Salvo, S. G. History of Massage Therapy. Massage Therapy-E-Book: Principles and Practice. 2015.
6 Moyer CA, Rounds J, Hannum JW. A meta-analysis of massage therapy research. Psychol Bull. Jan 2004;130(1):3–18. doi:10.1037/0033-2909.130.1.3 14717648
7 Swedish Institue College of Health Sciences. https://www.swedishinstitute.edu/history/
8 Taylor SL, Gelman HM, DeFaccio R, . We Built it, But Did They Come: Veterans’ Use of VA Healthcare System-Provided Complementary and Integrative Health Approaches. J Gen Intern Med. Mar 2023;38(4):905–912. doi:10.1007/s11606-022-07889-4
9 Veterans Health Administration. VHA Directive 1137. 2017.
10 Miake-Lye I, Lee J, Lugar T, . Massage for Pain: An Evidence Map. 2016. https://www.ncbi.nlm.nih.gov/pubmed/28211657
11 Miake-Lye IM, Mak S, Lee J, . Massage for Pain: An Evidence Map. J Altern Complement Med. May 2019;25(5):475–502. doi:10.1089/acm.2018.0282 30892910
12 Guimarães JS, Arcanjo FL, Leporace G, . Effects of therapeutic interventions on pain due to plantar fasciitis: A systematic review and meta-analysis. Clin Rehabil. Dec 26 2022:2692155221143865. doi:10.1177/02692155221143865
13 Candy B, Armstrong M, Flemming K, . The effectiveness of aromatherapy, massage and reflexology in people with palliative care needs: A systematic review. Palliat Med. Feb 2020;34(2):179–194. doi:10.1177/0269216319884198 31659939
14 The GRADE Working Group. Grading of recommendations assessment, development and evaluation (GRADE).
15 AHRQ. Evidence-based Practice Center. https://www.ahrq.gov/research/findings/evidence-based-reports/index.html
16 He Y, Guo X, May BH, . Clinical Evidence for Association of Acupuncture and Acupressure With Improved Cancer Pain: A Systematic Review and Meta-Analysis. JAMA Oncol. Feb 1 2020;6(2):271–278. doi:10.1001/jamaoncol.2019.5233 31855257
17 Kannan P, Lam HY, Ma TK, Lo CN, Mui TY, Tang WY. Efficacy of physical therapy interventions on quality of life and upper quadrant pain severity in women with post-mastectomy pain syndrome: a systematic review and meta-analysis. Qual Life Res. Apr 2022;31(4):951–973. doi:10.1007/s11136-021-02926-x 34185226
18 Ughreja RA, Venkatesan P, Balebail Gopalakrishna D, Singh YP. Effectiveness of myofascial release on pain, sleep, and quality of life in patients with fibromyalgia syndrome: A systematic review. Complement Ther Clin Pract. Nov 2021;45:101477. doi:10.1016/j.ctcp.2021.101477 34507243
19 Chou R, Wagner J, Ahmed AY, . AHRQ Comparative Effectiveness Reviews. Treatments for Acute Pain: A Systematic Review. Agency for Healthcare Research and Quality (US); 2020.
20 Guo Y, Lv X, Zhou Y, . Myofascial release for the treatment of pain and dysfunction in patients with chronic mechanical neck pain: Systematic review and meta-analysis of randomised controlled trials. Clin Rehabil. Oct 27 2022:2692155221136108. doi:10.1177/02692155221136108
21 Guzmán Pavón MJ, Cavero Redondo I, Martínez Vizcaíno V, Ferri Morales A, Lorenzo García P, Álvarez Bueno C. Comparative Effectiveness of Manual Therapy Interventions on Pain and Pressure Pain Threshold in Patients With Myofascial Trigger Points: A Network Meta-analysis. Clin J Pain. Dec 1 2022;38(12):749–760. doi:10.1097/ajp.0000000000001079 36350630
22 Smith CA, Hill E, Denejkina A, Thornton C, Dahlen HG. The effectiveness and safety of complementary health approaches to managing postpartum pain: A systematic review and meta-analysis. Integr Med Res. Mar 2022;11(1):100758. doi:10.1016/j.imr.2021.100758 34485073
23 Wu Z, Wang Y, Ye X, . Myofascial Release for Chronic Low Back Pain: A Systematic Review and Meta-Analysis. Front Med (Lausanne). 2021;8:697986. doi:10.3389/fmed.2021.697986 34395477
24 Zimpel SA, Torloni MR, Porfírio GJ, Flumignan RL, da Silva EM. Complementary and alternative therapies for post-caesarean pain. Cochrane Database Syst Rev. Sep 1 2020;9(9):Cd011216. doi:10.1002/14651858.CD011216.pub2 32871021
25 Mai QL, Li XJ, Yang D, Zhang XY, Peng K, Hao YF. Effects of acupressure on cancer-related pain management: A systematic review and meta-analysis of randomized controlled trials. Article. Eur J Integr Med. Apr 2022;51:9. 102120. doi:10.1016/j.eujim.2022.102120
26 Li T, Li X, Huang F, Tian Q, Fan ZY, Wu S. Clinical Efficacy and Safety of Acupressure on Low Back Pain: A Systematic Review and Meta-Analysis. Evid Based Complement Alternat Med. 2021;2021:8862399. doi:10.1155/2021/8862399 33708260
27 Skelly AC, Chou R, Dettori JR, . AHRQ Comparative Effectiveness Reviews. Noninvasive Nonpharmacological Treatment for Chronic Pain: A Systematic Review Update. Agency for Healthcare Research and Quality (US); 2020.
28 Yang J, Zhou X, Ma QY, . Efficacy and safety of Tuina for chronic nonspecific low back pain: A PRISMA-compliant systematic review and meta-analysis. Review. Medicine. Mar 2023;102(9):11. doi:10.1097/md.0000000000033018
29 Lavazza C, Galli M, Abenavoli A, Maggiani A. Sham treatment effects in manual therapy trials on back pain patients: a systematic review and pairwise meta-analysis. BMJ Open. May 4 2021;11(5):e045106. doi:10.1136/bmjopen-2020-045106
30 Li H, Liu H. Combined effects of acupuncture and auricular acupressure for relieving cancer-related fatigue in patients during lung cancer chemotherapy: A protocol for systematic review and meta-analysis. Medicine (Baltimore). Oct 22 2021;100(42):e27502. doi:10.1097/md.0000000000027502 34678883