# DISCUSSION

Our evidence map includes 15 new systematic reviews published since July 2018, and from these, 6 reviews reported moderate certainty of evidence for beneficial effect of massage therapy for pain. Most of these conditions were also represented in the previous evidence map. Post-breast cancer surgery pain is a newly identified condition with moderate certainty of evidence that myofascial release compared to sham has a potential beneficial effect on pain.^17^ There was a variety of massage therapy techniques included in the primary studies of included reviews, but inconsistent reporting of details about the interventions (eg, frequency, duration, follow-up) made it difficult to provide further synthesis of the data regarding the delivery of massage therapy for pain. An implication of this ambiguity is that translating this research into practice is challenging, since the provider needs to know what type of massage therapy was used for which condition and at what frequency/duration to deliver it in a clinical setting. The ongoing VERDICT trial is attempting to determine this kind of “dose” information for chiropractic care; a similar effort is needed for massage therapy.

Massage therapy is a broad term that is inclusive of many styles and techniques. We applied exclusion criteria determined a priori to help identify publications for inclusion in the evidence map. Despite that, there was still a lack of clarity in determining “what is massage therapy.” For instance, acupressure is sometimes considered acupuncture and other times considered massage therapy, depending on author definition. We encountered this situation in a separate evidence map of acupuncture, in which we found acupressure studies labeled as a type of acupuncture in acupuncture reviews. We excluded these primary studies of acupressure from the acupuncture evidence map. Similarly, we came across acupressure studies within reviews of acupuncture in the current search. In this case, we only reviewed and included publications that were explicitly labeled acupuncture and acupressure and did not review any publications about acupuncture only. This highlights a fundamental issue with examining the evidence base of massage therapy for pain when there is ambiguity in defining what is considered massage therapy.

Another limitation is the use of sham/placebo treatment as a comparison group for massage therapy. Most reviews did not specify what the sham treatment entailed. For reviews that did include additional details, sham was listed as “sham short-wave diathermy, and ultrasound,”^18^ “sham dry needling,”^18^ or “sham myofascial release.”^21^ It is conceivable that even the “light touch” or touch “with no clear criterion”^29^ used in sham massage therapy may have some positive effect, meaning that patients who receive the massage therapy intervention and those who receive a sham massage therapy both could demonstrate some degree of symptom improvement. In other words, unlike a pharmaceutical placebo, sham massage therapy may not be truly inactive. Use of a partially active sham condition tends to attenuate observed treatment effects: between-group differences in the outcome are smaller than they would be if the sham condition had been truly inactive. Without further details regarding sham/placebo treatments, findings from systematic reviews with primary studies comparing massage therapy versus sham/placebo should be interpreted with caution, and these findings may not be as informative or useful compared to an effect detected from active therapy/usual care studies. Moreover, limitations of sham comparators raise the question of whether sham/placebo treatment is an appropriate comparison group in massage therapy trials. It may be more informative to compare massage therapy to other treatments that are accessible and whose benefits are known, so that any added beneficial effect of massage therapy could be better isolated and understood.

Because all conclusions were rated low or very low certainty of evidence in the previous review, having identified 6 moderate certainty of evidence conclusions suggests there may be a stronger evidence base for the potential benefit of massage therapy now than in 2018. However, all 6 conclusions were drawn from analyses completed with fewer than 10 primary studies in each of the respective reviews. In addition, only 3 of the 6 reviews included primary studies published in or after 2018. Reviews by Ughreja et al about the effect of myofascial release on fibromyalgia,^18^ by Li et al about the effect of acupressure compared to active therapy on low back pain,^26^ and by Skelly et al about the short- and intermediate-term effect of massage therapy on chronic low back pain^27^ did not include any primary studies published after 2018. Guzmán Pavón et al included 8 primary studies about massage therapy for treatment of myofascial pain, of which 3 studies were published in and after 2018;^21^ Wu et al included 4 of 8 studies published since 2018 about myofascial release for chronic low back pain;^23^ and Kannan et al include 2 studies about myofascial release for post-breast cancer surgery pain, of which 1 study was published in 2018.^17^ This means no studies in the first 3 reviews and only about 50% of primary studies in the latter 3 reviews are considered “new” evidence which contributed to the higher certainty of evidence rating since our last literature search.

Despite these limitations, the moderate certainty of evidence conclusions identified in the current review of massage therapy’s potential benefit for back pain (including chronic low back pain and chronic back pain), fibromyalgia, myofascial pain, and breast-cancer-related pain represent a step in the right direction toward establishing a stronger evidence base for effect of massage therapy on pain, but more work in producing high-quality RCTs needs to be done to advance the field. It is only when systematic reviews and meta-analyses are conducted with high-quality primary studies that the effects or lack of effects of massage therapy on pain will reach higher certainties of evidence. For any conclusion of potential benefit, a high certainty of evidence rating means “we are very confident that the true effect lies close to that of the estimate of the effect.”^30^

## LIMITATIONS

There are two main limitations to this evidence map. The first, common to all systematic reviews, is that we may not have identified all the potentially eligible evidence. If a systematic review was published in a journal not indexed in any of the 5 databases we searched, and we did not identify it as part of our search of references of included publications, then we would have missed it. Nevertheless, our search strategy did identify more than 200 publications about massage therapy for pain published since July 2018, so we did not suffer from a lack of potential reviews to evaluate.

The second limitation of evidence maps is that we did not independently evaluate the source evidence; in other words, we took the conclusions of the authors of the systematic review “at face value.” That is the nature of an evidence map. Particular to this application of the mapping process, for the 1 health condition that had more than 1 eligible review (ie, back pain), we only mapped the review we deemed most informative. This necessarily requires judgment, and others could disagree with that judgment. We included the citation for the review excluded from the map for this “overlap” reason in Appendix B, and interested readers can review it for additional information. As in all evidence-based products, and particularly in one such as this covering a large and complex evidence base, it is possible that there are errors of data extraction and compilation. We used dual review to minimize the chance of such errors, but if we are notified of errors, we will correct them.

## FUTURE RESEARCH

The vast majority of the conclusions of the eligible systematic reviews were classified as low or very low certainty of evidence, indicating that the most critical research need is for better evidence to increase certainty of evidence for massage therapy for pain. Studies comparing massage therapy to placebo or sham are probably not the priority; rather the priority should be studies comparing massage therapy to other recommended/accepted/active therapies for pain. Studies comparing massage therapy to other recommended therapies should also have a sufficiently long follow-up time period to allow any non-specific effects (eg, of getting something “new”) to dissipate. For example, for studies of chronic pain, this time period has been proposed to be at least 6 months.

Furthermore, the importance of reporting sufficient details about massage therapy as the intervention of interest, as well as details about the comparison group, cannot be overstated. The type and schedule of massage therapy needs careful documentation so findings can be applied in other settings. In addition, although adverse events from massage therapy for pain appear to be rare, instituting more consistent and standardized reporting of adverse events in clinical trials will provide additional insights to the application and appropriateness of massage therapy as a non-pharmacological treatment for pain.

For painful conditions of priority to the VA that currently do not have at least moderate-certainty evidence supporting use of massage therapy, new studies that address limitations of existing research are needed. The field of massage therapy would be best advanced by educating the wider research community with clearer definitions of “massage therapy” and whether it is appropriate to include multiple modalities in the same systematic review.

## CONCLUSIONS

There is a paucity of systematic reviews of massage therapy for pain. Although the number of conclusions about the effectiveness of massage therapy that were judged to have at least moderate certainty of evidence is greater now than in 2018, but it is still small relative to the need. More high-quality randomized controlled trials are needed to provide a stronger evidence base to assess the effect of massage therapy on pain.