# RESULTS

## LITERATURE FLOW

The literature flow diagram (Figure 1) summarizes the results of the study selection process (the full list of excluded studies is available in Appendix B).

Figure 1 Literature Flowchart

## LITERATURE OVERVIEW

We identified 1,164 potentially relevant citations (Figure 1). We applied the inclusion and exclusion criteria to these titles and excluded 704 titles. A total of 460 abstracts were reviewed at abstract stage. From these, a total of 345 abstracts were excluded for the following reasons: not about pain (N = 195), not a systematic review (N = 73), not an intervention of interest (N = 45), not a condition of interest (N = 8), background (N = 7), duplicate (N = 5), not adults (N = 5), systematic review of qualitative studies (N = 5), and self-delivered therapy (N = 2). This left a total of 115 publications for review at full-text stage. A total of 75 publications were excluded at this stage because the authors did not state or cite the method used to formally assess the certainty or strength or quality of the evidence and 2 publications were unavailable. See Appendix B for a full list of excluded reviews. A total of 38 publications were retained for further review and potential inclusion on the map. Of these, 23 publications were excluded from the map for the following reasons: only 1 primary study about interventions of interest (N = 11), unable to distinguish effect for massage therapy from other included interventions (N = 5), not an intervention of interest (N = 3), not a comparison of interest (N = 2), not selected for map in favor of better review (N = 1), and self-delivered therapy (N = 1). We included 15 publications in this map. See Appendix C for more details about the included reviews.

### Characteristics of Included Reviews

The number of primary studies about massage therapy for pain in the included reviews ranged from 2 studies to 23 studies. Ten reviews included fewer than 10 primary studies,^12,16–24^ and 5 reviews included 10 to 25 studies about massage therapy for pain.^13,25–28^ One of the included reviews was completed by the Cochrane Collaboration,^24^ and 2 reviews were completed by the AHRQ EPC program.^19,27^

The country of origin for reviews varied, with the largest number of reviews originating from China (N = 4),^17,20,23,26^, followed by the US (N = 2),^19,27^ Brazil (N = 2),^12,24^ Australia (N = 1),^22^ England (N = 1),^13^ and India (N = 1).^18^ Four reviews were conducted by authors from multiple countries: China and Australia,^16^ China and Iran,^25^ China, Korea, and the US,^28^ and Spain, Chile, and Paraguay.^21^

Of the 15 included reviews, 2 reviews included more than 1 type of massage therapy and 13 reviews included only 1 type of massage therapy. The reviews by Chou et al and Smith et al both included acupressure and massage therapy (not otherwise specified) or mixed massage therapy as interventions.^19,22^ Of the 13 reviews with only 1 type of massage therapy, 4 reviews described massage therapy (not otherwise specified) or mixed massage therapy,^13,21,24,27^ 1 review was about Tuina,^28^ 5 reviews were about myofascial release,^12,17,18,20,23^ 2 reviews were about acupressure,^25,26^ and 1 review was about auricular acupressure.^16^

Since we excluded reviews that explicitly stated massage therapy was self-delivered, any review that did not specify the mode of delivery was included. Three of the 15 included reviews provided details of personnel who administered the therapy, including massage therapist, nurse, aromatherapist, physiotherapist, and reflexologist.^13,18,22^

There was substantial variation in the reporting of details from the primary studies in the included reviews. Most reviews presented length of sessions, from 5- to 90-minute sessions for massage therapy studies and 30-seconds to 5-minute sessions for acupressure studies. With the exception of the review by He et al,^16^ all reviews reported details about frequency and/or duration when available. From reviews that included frequency information, we found a range from 1 session only to once every 3 weeks for massage therapy studies, and 4 times a day to daily for acupressure studies. For duration, some reviews reported interventions lasted from one session only to 3 months. Seven reviews included details about follow-up (eg, 1 week, 12 months).^13,18,20,24,26–28^

A variety of comparators were included in the reviews. Six reviews included more than 1 comparator in their analyses.^18,19,21–23,27^ Of these, 1 review did not conduct separate analyses by comparator (labeled “mixed with no subgroups”)^21^ and 2 reviews did conduct separate analyses by comparator (labeled “mixed with subgroups”);^18,23^ the other 3 reviews included a mix of comparators: sham/placebo and active therapy/usual care,^19^ mixed with no subgroups and active therapy/usual care,^27^ and mixed with subgroups and active therapy/usual care.^22^ Eight reviews described interventions compared to active therapy/usual care only,^12,13,16,20,24–26,28^ while 1 review limited inclusion to primary studies with a sham or placebo comparator.^17^

We categorized the included 15 reviews into health conditions with pain as an outcome. Conditions include cancer-related pain,^16,25^ back pain (including chronic back pain,^23,28^ chronic low back pain,^27,20^ and low back pain),^26^ chronic neck pain,^27^ fibromyalgia,^18^ mechanical neck pain,^20^ myofascial pain,^21^ palliative care needs,^13^ post-breast cancer surgery,^17^ post-caesarean pain,^24^ post-partum pain,^22^ and post-operative pain.^19^

Five reviews were mapped more than once. Skelly et al included chronic low back pain with short-term effect and intermediate-term effect, as well as neck pain in their review;^27^ Li et al included several active therapies as comparators resulting in different certainty of evidence conclusions;^26^ Candy et al included both reflexology and massage therapy in their review about palliative care needs;^13^ Chou et al included different comparators (sham and active therapy) and interventions (massage therapy and acupressure) in their review about post-operative pain;^19^ and Smith et al included both acupressure and massage therapy in their review about post-partum pain.^22^

We mapped conclusion(s) for the effect of massage therapy on the conditions that were also included in the previous evidence map: back pain (including chronic low back pain and chronic back pain), cancer-related pain, fibromyalgia, myofascial pain, neck pain (including chronic neck pain and mechanical neck pain), palliation-related pain, and post-operative pain (Table 1).

Table 1 Conditions in Both 2018 and 2023 Evidence Maps

Condition | Primary Studies Published Since 2018 | # of Reviews for the Condition
Back pain (including chronic low back pain and chronic back pain) | 16 | 4
Cancer-related pain | 13 | 2
Fibromyalgia | 0 | 1
Myofascial pain | 3 | 1
Neck pain (including chronic neck pain and mechanical neck pain) | 0 | 2
Palliation-related pain | 1 | 1
Post-operative pain | 2 | 1

We surveyed the publication year of the primary studies included in the 11 reviews about these 7 conditions to assess the number of new trials published in or after 2018. With the exception of fibromyalgia,^18^ the other 6 conditions were represented by reviews which had included primary studies that were published in 2018 or after. For back pain, 16 studies from 3 reviews were published since 2018: myofascial release for chronic back pain (N = 4),^23^ Tuina for chronic back pain (N = 7),^28^ and acupressure for low back pain (N = 5).^26^ A fourth review about the short and intermediate-term effect of massage therapy for chronic low back pain did not include trials published since 2018.^27^ For cancer-related pain, 13 studies about acupressure from 1 review were published since 2018.^25^ No primary studies contributing to the potential benefit of auricular acupressure for cancer-related pain were published prior to 2018.^16^ For myofascial pain, 3 studies about massage therapy from 1 review were published since 2018.^21^ For neck pain, 7 studies about myofascial release from 1 review were published since 2018.^20^ A second review about massage therapy for neck pain did not include trials published since 2018.^27^ For palliation-related pain, 1 review had included 1 primary study about reflexology which was published in 2018.^13^ For post-operative pain, 2 reviews about massage therapy were published since 2018.^19^

This map includes 4 conditions that were not part of the previous map (Table 2).

Table 2 Newly Identified Conditions in 2023 Evidence Map

Condition | Primary Studies Published Since 2018
Plantar fasciitis | 2
Post-breast cancer surgery | 1
Post-caesarean pain | 2
Post-partum pain | 2

Eleven conditions were included the previous map but are not in the current report: arthritis, cervical radiculopathy, dysmenorrhea, elbow pain, headache, labor pain, mixed musculoskeletal pain, muscle soreness, pain in critical care setting, scar pain, shoulder pain, and temporomandibular joint pain. We did not identify citations about arthritis, cervical radiculopathy, or muscle soreness in the update search to be reviewed at full text. Table 3 provides details for the other 8 conditions.

Because we applied an additional criterion that reviews had to report a method used for grading certainty of evidence to be included in this map, a few conditions that had appeared in the previous map were not included in this map. Some publications were excluded due to only including 1 primary study with an intervention of interest; 1 publication did not include pain as an outcome of interest; and other reviews did not separate the analysis of the effect of different treatments for a condition, which means we were unable to distinguish the effect for massage therapy from other included interventions.

Table 3 Selected Conditions in Previous Evidence Map Not in 2023 Evidence Map

Condition | New Systematic Review Identified in Update Search? | Exclusion Reason
Arthritis | No | N/A
Cervical radiculopathy | No | N/A
Critical care | 1 | - No certainty of evidence rating (N = 1)
Dysmenorrhea | 5 | - No certainty of evidence rating (N = 4); - Included only 1 primary study of interest (N = 1)
Elbow | 1 | - No certainty of evidence rating (N = 1)
Headache | 5 | - No certainty of evidence rating (N = 2); - Included only 1 primary study of interest (N = 1); - 2 not separate
Labor | 3 | - No certainty of evidence rating (N = 1)
Mixed musculoskeletal
Knee osteoarthritis | 7 | - No certainty of evidence rating (N = 6); - Unable to distinguish effect for massage therapy from other included interventions (N = 1)
Carpal tunnel syndrome Acute/chronic | 1 | - Included only 1 primary study of interest (N = 1)
Carpal tunnel syndrome Acute/chronic | 3 | - No certainty of evidence rating (N = 3)
Muscle soreness | No | N/A
Scar | 3 | - No certainty of evidence rating (N = 1); - No outcome of interest (N = 1)
Shoulder | 1 | - No certainty of evidence rating (N = 1)
Temporomandibular joint | 2 | - No certainty of evidence rating (N = 1); - Included only 1 primary study of interest (N = 1)

## EVIDENCE MAP

In the evidence map, columns correspond to whether a conclusion of the review was that 1) there was a potential benefit of massage therapy relative to a comparison treatment, or 2) there was no benefit of massage therapy relative to the comparison treatment. Columns are not mutually exclusive: a review could have more than 1 conclusion for separate comparators or type of massage therapy, and those conclusions could differ in the potential benefit of massage therapy.

Rows correspond to GRADE ratings of certainty of evidence:^14^

- High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.
- Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
- Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.
- Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

In contrast to columns, all rows are mutually exclusive. The top row indicates that the review’s conclusion about massage therapy for pain as rated by its authors have high (or strong) certainty of evidence. The middle row indicates that the review’s conclusion about massage therapy for pain was rated as moderate certainty of evidence (and none rated as high or strong, in which case it would be in the top row). The bottom row indicates that the review’s conclusion about massage therapy for pain was rated as low or very low certainty of evidence. Since GRADE assesses certainty of evidence, it is possible for a body of evidence to demonstrate low or moderate estimates of effect but with high certainty of evidence; conversely, it is possible to have evidence with large effect sizes but with low certainty.

Each conclusion is then mapped onto this framework and identified by the name of the condition, eg, “chronic back pain,” “fibromyalgia,” “post-operative pain,” etc. Shapes are used to distinguish between the types of comparison treatments: conclusions only about comparisons to sham/placebo, conclusions only about comparisons to active therapy/usual care, conclusions where the comparison treatments were a mix of these and no subgroup analysis was presented, and conclusions where comparison treatments were a mix of these with subgroup analyses. Symbols are used to identify the conclusions specific to massage therapy (eg, Tuina, myofascial release, reflexology, massage therapy—not otherwise specified) or acupressure (ie, including auricular acupressure).

The size of the bubble is used to indicate how many original research studies were included in the review about massage therapy for pain: the smallest bubble denotes reviews with 2–5 primary studies included, the medium bubble with a pattern of diagonal lines denotes reviews with 6–9 primary studies included, and the largest bubble denotes reviews with 10 or more primary studies included.

For example, in Figure 2, the large orange hexagon in the middle column of the bottom row indicates that there is a review about chronic back pain that included 10 or more original studies and had a conclusion rated as low or very low certainty of evidence that message therapy was better than the comparison treatment of active therapy/usual care/control. In the same figure, the small blue circle in the lower right-hand corner indicates that there is a review about post-partum pain that included 2 to 5 original studies and had a conclusion rated as low or very low certainty of evidence that acupressure was not of greater benefit than the comparison treatment of mixed therapies with subgroups.

Figure 2 Evidence Map

There were 5 reviews with more than 1 conclusion about effect of massage therapy on pain and were mapped twice, denoted by an asterisk after the health condition.^13,19,22,26,27^

In addition to this map, we collected all certainty of evidence conclusions about massage therapy for pain in Table 4. There are 6 systematic reviews that described conditions that had moderate certainty of evidence conclusions for the potential benefit of massage therapy by the original review authors. All the remaining conclusions were judged by the original authors as being low or very low certainty of evidence, meaning “Our confidence in the effect estimate is limited. The true effect may be substantially different from the estimate of effect” or “We have very little confidence in the effect estimate.”

Table 4 Certainty of Evidence Conclusions from Systematic Reviews Included in the Evidence Map

Author, Year | Condition | Certainty of Evidence Conclusion
Moderate Certainty of Evidence Conclusions
Wu, 2021^23^ | Chronic low back pain | Compared to sham or active therapy, myofascial release significantly improved pain in patients with chronic low back pain.
Skelly, 2020^27^ | Chronic low back pain (short-term) | Compared to sham and active therapy/usual care, massage therapy was associated with small, short-term improvements in pain.
Ughreja, 2021^18^ | Fibromyalgia | Compared to sham or active therapy, myofascial release has effect on pain.
Li, 2021^26^ | Low back pain | Compared to active therapy (physical therapy), there was evidence of pain relief using acupressure for low back pain.
Guzman Pavon, 2022^21^ | Myofascial pain | Compared with no treatment, placebo, and active therapies, massage therapy had a greater effect on pain.
Kannan, 2022^17^ | Post-breast cancer surgery | Compared to placebo, there were positive treatment effects for myofascial release on pain.
Low or Very Low Certainty of Evidence Conclusions
He, 2020^16^ | Cancer-related pain | Compared to active therapy, auricular acupressure was associated with reduced pain intensity.
Mai, 2022^25^ | Cancer-related pain | Compared to usual care, acupressure demonstrated a reduction in pain intensity.
Yang, 2023^28^ | Chronic back pain | Compared to active therapy, Tuina might be an effective and safe strategy for treating chronic low back pain in terms of pain.
Skelly, 2020^27^ | Chronic low back pain (intermediate-term) | Compared to sham and active therapy/usual care, massage therapy has no difference in intermediate-term improvements in pain.
Skelly, 2020^27^ | Chronic neck pain | Compared with attention or waitlist control, massage therapy was associated with a small to moderate improvement in short-term pain.
Li, 2021^26^ | Low back pain | Compared to active therapy or usual care, acupressure could provide clinical benefits to low back pain conditions and had a significant short-term response rate in low back pain management.
Guo, 2023^20^ | Mechanical neck Pain | Compared to active therapy, myofascial release had no significant difference between MFR and conventional intervention for mechanical neck pain.
Candy, 2020^13^ | Palliative care needs | Compared to active control, there was some evidence that reflexology reduced pain.; Compared to active therapy, evidence on the effectiveness of massage therapy in reducing pain was inconclusive.
Guimarães, 2022^12^ | Plantar fasciitis | Compared to the control in the short-term, there is low certainty of evidence of myofascial release resulting in effective treatment for pain.
Zimpel, 2020^24^ | Post-caesarean pain | Compared to active therapy, we are uncertain if hand and foot massage therapy plus analgesia has any effect on pain.
Chou, 2020^19^ | Post-operative pain | Compared to sham, acupressure is effective for post-operative pain.; Compared to active therapy, massage therapy is effective for post-operative pain with decreased pain medication use at <1 week.
Smith, 2022^22^ | Post-partum pain | Compared to active or routine care, there was a reduction in pain from massage therapy following recovery from caesarean birth within 24 hours and at 7 days.; Compared to sham or routine care, acupressure studies found no improvement in pain.

Three high-level observations can be made from the evidence mapping process:

First, our update search identified 6 reviews describing conditions with moderate certainty of evidence of potential benefit from reviews published since July 2018. There were only reviews with conclusions of low and very low certainty of evidence in the last review. This suggests there is a stronger evidence base for the potential benefit of massage therapy for pain in some conditions since the last synthesis of literature.

Second, only about 13% of reviews (2 of 15) included more than 10 primary studies; 53% (8 of 15) reviews included between 2 and 5 studies as the basis for their conclusions about massage therapy for pain. This means a majority of the conclusions about the potential benefit for massage therapy were drawn from a small number of primary studies.

Third, 5 of 6 reviews with moderate certainty of evidence included analyses comparing massage therapy to more than 1 comparison group. Kannan et al compared myofascial release to sham only.^17^ Except for the review by Li et al,^26^ the other reviews all included sham or placebo as a comparison group. Since manual therapies like massage therapy require some form of touching, without further details about what “sham” or “placebo” treatment entailed in these primary studies, the effect of massage therapy detected from only sham/placebo studies should be interpreted with caution and may not be as informative or useful compared to an effect detected from active therapies studies. Two reviews on chronic low back pain^27^ and myofascial pain^21^ did not conduct separate analyses by comparison condition, so it is unclear whether the reported benefits of massage therapy indicate that massage therapy is superior to other treatment approaches for these conditions, or that the observed effects of massage therapy are driven mainly by a comparison to no treatment (in which any active treatment would be expected to have some effect). Three reviews about chronic low back pain,^23^ fibromyalgia,^18^ and low back pain^26^ did conduct separate analyses by comparator, and in these reviews, beneficial effects of massage therapy were apparent in comparisons to sham/placebo as well as to active therapy.

### Adverse Events

Evidence about adverse events was collected by about half of the included reviews and no serious adverse events were reported. While 9 of 15 reviews described adverse events, only 2 reviews included certainty of evidence conclusions for adverse events.

In a review about post-caesarean pain, the authors reported data for adverse events in the form of “anxiety assessed by different scores with the use of massage therapy at 90 minutes after the intervention and at 60 minutes after the intervention.”^24^ It is uncertain if there was a difference between groups, and the authors rated this conclusion very low certainty of evidence. In another review about low back pain, <1% to 26% of participants reported additional pain after receiving massage therapy.^27^ The authors found no difference between groups for pain experienced post-massage therapy and rated this conclusion low certainty of evidence. The same review also included neck pain. There were reports of mild adverse effects such as discomfort or pain during or after Swedish massage therapy, increased pain after Tuina, or “dizziness, sleepiness, mood swings, nausea, difficulty staying asleep, difficulty moving the head and neck.”^27^ The authors found no difference between groups for these adverse events and rated this conclusion low certainty of evidence.