# METHODS

## TOPIC DEVELOPMENT

This topic was developed in response to a nomination from Juli Olson, DC, DACM, National Lead for Acupuncture, Integrative Health Coordinating Center; Sharon M. Weinstein, MD, MT, FAAHPM, VA National Lead of Massage Therapy, Integrative Health Coordinating Center; and Alison Whitehead, MPH, C-IAYT, E-RYT200, National Lead for Integrative Health Coordinating Center. The scope was further developed with input from the topic nominator, the ESP Coordinating Center, and the review team. The scope of this report includes: 1) One or more evidence maps that provide a visual overview of the distribution of evidence for massage therapy for pain, and 2) an accompanying narrative that helps stakeholders interpret the state of the evidence to inform policy and clinical decision-making.

## DATA SOURCES AND SEARCHES

Search strategies were based on those used for the original ESP evidence map of massage therapy^10^ and subsequent journal article,^11^ which included literature published through June 2018. Five databases were searched for relevant records published from July 2018 to April 2023: PubMed, Allied and Complementary Medicine Database (AMED), Cumulated Index to Nursing and Allied Health Literature (CINAHL), Cochrane Database of Systematic Reviews (CDSR), and Web of Science. See Appendix A for full search strategies.

## STUDY SELECTION

Eligible publications were systematic reviews of studies that examined the efficacy or effectiveness of massage therapy for pain in adults. In general, any therapist-delivered modality described as “massage therapy” by review authors was considered eligible; these included acupressure, Tuina, Thai, Swedish, myofascial release, etc. Sports massage therapy, osteopathy, dry cupping/dry needling, and internal massage therapy (eg, for pelvic floor pain) were ineligible, however, as were self-administered massage therapy techniques like foam rolling. Studies were required to compare massage therapy to a sham/placebo massage, usual care, or other active therapies (exercise, physical therapy, etc). Reviews that included studies of other interventions were eligible if results for massage therapy were reported separately. Examples of such reviews are: Effects of Therapeutic Interventions on Pain Due to Plantar Fasciitis: A Systematic Review and Meta-Analysis^12^ or The Effectiveness of Aromatherapy, Massage and Reflexology in People with Palliative Care Needs: A Systematic Review.^13^

Titles of potentially eligible reviews were screened for relevance by 2 authors independently; any article chosen by either reviewer was included in the abstract screen. Abstracts were then reviewed in duplicate, with any discrepancies resolved by group discussion. We recorded condition type when reviewing abstracts and presented a list of conditions for which we found reviews to the Operational Partners to determine which conditions were of interest to the VA. Operational Partners elected to focus only on pain for the evidence map. Any conditions not selected were then excluded. Reviews that did not employ systematic methods for identifying and critically appraising studies were also excluded.

We next restricted eligibility to reviews that used formal methods to assess the certainty (or strength or quality) of the evidence for conclusions. In most reviews, this involved use of the Grading of Recommendations, Assessment, Development and Evaluations (GRADE) approach.^14^ However, other formal methods were accepted, such as the approach developed by the Agency for Healthcare Research & Quality (AHRQ) Evidence-based Practice Center (EPC) program.^15^ To remain eligible, a systematic review had to 1) state or cite the method used to formally assess the certainty (or strength or quality) of included evidence, and 2) report the certainty (or strength or quality) of evidence for the effect of massage therapy on pain.

After applying this restriction, almost all health conditions had only 1 systematic review meeting eligibility criteria, and we included this review in the map. Back pain was the only health condition with multiple reviews meeting eligibility criteria. For this condition, we first assessed whether the review differed in some other feature used to classify reviews on our map. For example, 1 systematic review on back pain included only studies comparing massage therapy to a mixed group of comparators, while another systematic review on back pain only included studies comparing massage therapy to other active therapies. In such cases, we included both reviews in the map, with the appropriate designations (such as “versus mixed with subgroups” and “versus active therapy/usual care”). If there were multiple reviews on the same condition and they did not differ in some other feature, then we selected the 1 systematic review that we judged as being most informative to stakeholders. In general, this was the most recent review or the review with the greatest number of included studies. Systematic reviews otherwise meeting eligibility criteria that were not included in the map for this reason are listed in Appendix B.

## DATA ABSTRACTION AND PRESENTATION

Each included systematic review had data abstracted by 1 reviewer and verified by a second reviewer. Abstracted data included, but were not limited to: number of studies included in the review that had massage therapy as the intervention, treated condition, type of massage therapy, comparators, certainty of evidence rating, and certainty of evidence conclusion(s) relevant to massage therapy as treatment for pain.

Our evidence mapping process resulted in a visual depiction of the evidence for massage therapy for pain, as well as an accompanying narrative with an ancillary figure and table. The visual depiction or evidence map uses a bubble plot format to display information on 4 dimensions: bubble size, bubble label, x-axis, and y-axis. This allowed us to provide the following types of information about each included systematic review, as follows:

Number of articles in systematic review (bubble size): The size of each bubble corresponds to the number of relevant primary research studies included in a systematic review.

Condition (bubble label): Each bubble is labeled with the condition discussed by that systematic review.

Shapes and colors: Intervention characteristics for each condition are presented in the form of colors (type of intervention) and shapes (comparators). For type of intervention, orange represents massage therapy and blue represents acupressure. Massage therapy may include singular interventions or a combination of massage therapy (not otherwise specified), Tuina, myofascial release, and/or reflexology. Acupressure may include auricular acupressure. For comparators, a circle denotes mixed comparators with subgroups, rectangle for mixed comparators with no subgroups, triangle for sham/placebo, and octagon for active/usual care. A condition can show up more than once if multiple systematic reviews included either different types of massage therapy and/or different comparators.

Strength of findings (rows): Each condition is plotted on the map based on the certainty of evidence statement as reported in the systematic review. We have 3 categories: “Conclusion is rated as low or very low certainty,” Conclusion is rated moderate certainty,” and “Conclusion is rated as high or strong certainty.”

Effect of massage therapy (columns): Each condition is plotted in either “potential benefit” or “no benefit” as effect of massage therapy based on conclusion of systematic review.

Narrative synthesis: The narrative synthesis expands upon the visual evidence map to provide overarching conclusions from the map. Details about the conclusions in individual reviews are included in the table.