# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) is responding to a request from the VHA Office of Patient Centered Care & Cultural Transformation, Integrative Health Coordinating Center to provide current evidence regarding use of massage therapy for pain as treatment for conditions of interest to the VA. Findings from this review will be used by VA referring providers, site leadership, and policy makers to improve Veteran access to non-pharmacologic treatment approaches and improve outcomes for Veterans by utilizing evidence-based care pathways.

## BACKGROUND

Massage therapy is a popular and widely accepted complementary and integrative health (CIH) modality for individuals seeking relief from pain.^1^ Massage therapy is the practice of manual assessment and manipulation of the superficial soft tissues of skin, muscle, tendon, ligament, fascia, and the structures that lie within the superficial tissues for therapeutic purpose.^2^ Individuals may seek massage therapy to address pain where conventional treatments may not always provide complete relief or may come with potential side effects. Massage therapy encompasses a range of techniques (eg, massage, acupressure, myofascial release), styles, (eg, sports massage, deep tissue, Tui Na, shiatsu), and duration (eg, 10-minute, hour-long).^3^ Massage therapists are uniquely trained, qualified, and credentialed to deliver massage therapy. Other health care professionals, such as physical therapists, chiropractors, nurses, and acupuncturists may provide massage therapy when properly trained and qualified.

Massage therapy has been part of many ancient cultures, with historical records predating 3000 BC.^4,5^ The field of massage therapy has evolved from being regarded as folk medicine in the Middle Ages to the introduction of Swedish massage therapy as a medical treatment by Johann Mezger in the late 1800s.^6^ The first massage therapy school in the United States was established in 1916 as the Swedish Gymnastic Institute in New York City for medical gymnastics and massage therapy.^7^ Despite its popularity and long history in practice, evidence of beneficial effect of massage therapy remains limited.

Massage therapy has seen a dramatic increase in the number of users and visits since 2016 across the Veterans Health Administration (VHA).^8^ Massage therapy has been part of Veterans’ standard medical benefits package under VHA Directive 1137 since 2017.^9^ Veterans utilize massage therapy for a variety of reasons and conditions, including relaxation, musculoskeletal pain, lymphedema, anxiety, and depressive symptoms.^8^ While there may be evidence supporting the use of massage therapy for other indications, the scope of this report was to focus on pain as an outcome. The last ESP evidence map of massage therapy for pain was published in 2016 with an accompanying review article published in 2019. VHA stakeholders were interested in new evidence since publication of the earlier review; thus, we conducted an update of the previous report and present a new evidence map of massage therapy for pain.