# APPENDIX D PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 2 | Yes | Thank you.
3 | 3 | Yes | Thank you.
4 | 4 | Yes | Thank you.
5 | 5 | Yes | Thank you.
6 | 7 | Yes | Thank you.
7 | 8 | Yes | Thank you.
8 | 9 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
9 | 1 | No | Thank you.
10 | 2 | No | Thank you.
11 | 3 | No | Thank you.
12 | 4 | No | Thank you.
13 | 5 | No | Thank you.
14 | 7 | No | Thank you.
15 | 8 | No | Thank you.
16 | 9 | Yes - sample bias, although the author recognized that on their limitations. my recommendations were included. At least from my conclusion, i will say “The number of conclusions about the short-term effectiveness of massage that were judged to have at least moderate certainty of evidence is greater now that in 2018, but still small relative to the need. Also if you try to compare the previous review with the new one, using xycbenefit” instead of “potential benefit” in my opinion mislead the reader. | We have revised the wording based on your suggestions.
Are there any published or unpublished studies that we may have overlooked?
17 | 1 | No | Thank you.
18 | 2 | No | Thank you.
19 | 3 | No | Thank you.
20 | 4 | No | Thank you.
21 | 5 | No | Thank you.
22 | 7 | No | Thank you.
23 | 8 | No | Thank you.
24 | 9 | Yes - Synthesizing the Strength of the Evidence of Complementary and Integrative Health Therapy for Pain. Giannitrapani, . Pain Medicine, 0(0), 2019, 1–10 .; see my comments in the review.; But, this is an article in a peer review journal with an Evidence map (including massage). The used the proper wording or “Evidence of a Potential Positive effect” or “Potential Benefit”. The majority of the evidence suggested Massage has unclear or mixed effect. Only a small group of article confirmed your finding regarding “chronic back pain”, “Chronic low back pain”, “Myofascial pain”. | Our search strategy was limited to publications that are systematic reviews. Since this publication is not a systematic review, it would not have been identified in our search.
Additional suggestions or comments can be provided below.
25 | 1 | Would it be possible to indicate the colors for the intervention in the key to the Evidence Map with some other shape rather than a circle. I found interpreting the map to be confusing with too many circles. Maybe a thin rectangle or some other shape. | We have updated the key.
26 | 1 | On page 2 in the Executive Summary the word Results is there on line 17/18. Is the rest of the sentence missing or just an error? I would like to see a sentence in the Executive Summary describing the colors, shapes and size key. Something like “Color denotes intervention type, shape denotes type of comparator and size indicates the number of studies included in the review”. Also listing an example would be helpful like in the text of the Evidence Report on page 14 line 6-15. If the reader is only reading the Executive Summary then the map is quite confusing without some additional explanation. | This has been edited, thank you.; We have added to sentence to the executive summary.
27 | 1 | I’m curious as to why the following reviews listed in Appendix B were not included in the analysis: Number 3 (chronic noncancer pain); 5 (Jung) & 6 (Kamonseki) for headache and 8 Wu et al regarding knee arthritis? Table lists this reason: “Not an Intervention of Interest”. Page 8 line 6,7 says that “The operational partner selected only painful conditions to be included the evidence map” Does this mean that headaches, non-cancer pain and knee arthritis aren’t painful conditions or was there another reason they were excluded? If there are other reasons then the table and text should be changed to reflect that. | This exclusion reason refers to the included interventions used for treatment of the respective conditions. These reviews did not separate the analysis of the effect of different treatments for a condition, which means we were unable to distinguish the effect for massage therapy from other included interventions. We have relabeled the exclusion reason for this group of publications to better describe the reason for exclusion.
28 | 1 | Page 10, line 61 reads “See Appendix B for more details about the included reviews”. I think you mean Appendix C. | This has been edited, thank you.
29 | 1 | Page 13: Text says “message” instead of “massage” in three different spots, line 30, 32, 35. | This has been edited, thank you.
30 | 2 | please consider using the term “massage therapy” consistently throughout the document, importantly here in this Executive Summary Key Findings | We have made edits to use the term “massage therapy” consistently throughout the document.
31 | 2 | Suggest clarification here, if the “sham/placebo” control in some studies included hands on contact (touching) without soft-tissue manipulation, that could have some therapeutic benefit, yes; would also clarify what was meant as “active therapies” if there is detail (exercise?) meaning the patient performed the activities | We added details in methods to clarify what “active therapies” could be.
32 | 2 | Not sure if you want to elaborate here that our VHA data being published showing benefits of these non-pharmacologic cares, such as Massage Therapy, has much broader implications for the health of the general US population, not only Veterans. | We have revised the introduction, thank you
33 | 2 | Prefer we use VA definition of Massage Therapy: “Massage Therapy is the practice of manual assessment and manipulation of the superficial soft tissues of skin, muscle, tendon, ligament, fascia, and the structures that lie within the superficial tissues for therapeutic purpose” | This has been edited, thank you.
34 | 2 | Here I would indicate that Massage Therapy comprises different techniques, styles, applications (sports massage, deep tissue, tui na, shiatsu, etc.); the word “modalities” implies something else. I would make the distinction that Massage Therapists are uniquely trained, qualified and credentialed to deliver Massage Therapy. Other health care professionals, such as physical therapists, chiropractors, nurses, and acupuncturists may provide manual therapy, massage, soft-tissue manipulation and acupressure when properly trained and qualified. | We have revised the introduction, thank you.
35 | 2 | notes - historical records predate 3000 BC; the first massage therapy school in the United States was established in 1916 as the Swedish Gymnastic Institute (NYC) - for Medical Gymnastics and Massage | We have revised the introduction, thank you.
36 | 2 | Please include my middle initial: Sharon M Weinstein, thank you | This has been added.
37 | 2 | typo - message, should read “massage,” suggest scan document for word “message” and correct as needed, thank you | This has been edited.
38 | 2 | please see prior comment about “sham/placebo” - hands on contact, or touch without soft-tissue manipulation may have therapeutic benefit, multiple contributing factors to pain relief, agree that without details of control intervention, interpretations of studies is limited | Thank you for your comment.
39 | 2 | massage is a general term not reflective of any one technique; in VHA we have defined Massage Therapy specifically (see previous comment); we refer to acupressure specifically as a defined technique; acupressure falls under the category of Massage Therapy as it is a manipulation of soft-tissue for a defined therapeutic purpose; acupressure is the point pressure manipulation (without needles) following the same theory on which acupuncture needling is based; important to include acupressure but not acupuncture as massage therapy for purposes of this review, if a study cannot separate them as treatments, I would hold it out | Thank you for your comment.
40 | 2 | I could not agree more; in studies the treatment technique/frequency/duration must be described in detail AND ALSO details of the pain condition(s) must be included; pain research has been generally flawed in that regard, “back pain” for example comprises multiple pathophysiologies, some of which will respond quite well to soft-tissue manipulation and others not as well -- will have better predictions for outcomes and adverse events from future studies hopefully with these inclusions in designs | Thank you for your comment.
41 | 2 | again, please consider using term “massage therapy” throughout, thank you | We had edited the document to use “massage therapy” throughout, thank you.
42 | 2 | I am curious why this review was held out for “not an intervention of interest” as it appears to me there was inclusion of massage therapy as the intervention ? | This review was excluded because we were unable to separate the effect of massage therapy for studies of interest from studies which had employed self-delivered massage therapy as treatment.
43 | 3 | Please use consistency in office name here: Integrative Health Coordinating Center VHA Office of Patient Centered Care and Cultural Transformation | This has been edited.
44 | 3 | Update Juli title to: National Lead Clinical Champion | This has been edited, thank you.
45 | 3 | Please update: Alison M. Whitehead, MPH, C-IAYT, E-RYT200 (and see office comment above) | This has been edited, thank you.
46 | 3 | which Coordinating Center? ESP? Might note that since the operational partners are all from Integrative Health Coordinating Center | This has been edited, thank you.
47 | 3 | perhaps note that there are other indications for massage therapy as well but this was focused on pain management | This has been edited, thank you.
48 | 3 | use massage therapy (instead of massage) throughout | We have edited this throughout, thank you.
49 | 3 | please update per above: Alison M. Whitehead, MPH, C-IAYT, E-RYT200 | This has been edited, thank you.
50 | 3 | sounds odd to say “painful conditions” do you mean “pain conditions”? | This has been edited, thank you.
51 | 4 | Please list Clinical Champion here as national role. | This has been edited, thank you.
52 | 4 | Maybe something about how there is other evidence for the usefulness of MT other than pain but this initial scope was to look only at pain as an outcome. | We have revised the introduction, thank you.
53 | 4 | The word results looks like a sentence fragment. | This has been edited, thank you.
54 | 4 | I think we should consider if we want to include reflexology as a massage therapy intervention here. | Upon discussion with the OPs, reflexology will be included as a massage therapy intervention.
55 | 4 | Maybe say from :“other interventions” instead of “active therapies”. Maybe it is a presumption that active therapy is a good comparison vs. usual care. | We have changed the label to “active therapies or usual care” throughout
56 | 4 | Again wonder if we should state in this area that massage may be used for conditions other than pain but this review is focused on pain and doesn’t exclude that there are other indications. | This has been edited, thank you.
57 | 4 | People use massage for things other than pain. Relaxation, lymphedema, etc. | The has been edited, thank you.
58 | 4 | This is the definition of MT that we use in VA: “Clinical massage therapy is the manipulation of the soft tissues of the human body for therapeutic purposes.” | The has been edited, thank you.
59 | 4 | I think I would use physical therapist over chiropractor here. | This has been edited, thank you.
60 | 4 | Add “for pain” at the end of this sentence - this is only for pain. | This has been edited, thank you.
61 | 4 | Again active therapies or usual care, not just active therapies. | We have changed the label to “active therapy/ usual care” throughout
62 | 4 | Might be helpful to have an overarching statement here that where evidence was collected about adverse events they were mild. I see that this is partially discussed later, but starting the paragraph with an assessment or ending the paragraph with an assessment based on the literature would be very helpful for the VA field. | We have added this statement, thank you.
63 | 5 | Great job. I felt this research was thorough. Thank you | Thank you for your comment!
64 | 7 | Indeed this is challenign as Massage therapy is credentially in carious ways in each country and state and region. The nomenclature of the specific techniques is also varied. It is vital that we continue this process and then build our staffing within VA to then be able to initiate more research. Massage therapists in the community often do not have the time, knowledge nor foudnation to create research into their techniques and results. Documentation of pain versus function also is a challenge. As we well know more often manyal techniques along with behavioral and exercise or movement otpimize outcomes. Many of us have been trained in manual techniques and various professional group have offered significant manual interventions (physiotherapy, occupational therapy, nursing, chiropractic, physician, kinesiotehrapy, massage therapy). Thank you for this work. I look forward to additional contributions based on medical massage interventions including aquatic massage and body work techniques. | Thank you for the comment.
65 | 9 | Should be Potential Benefit (instead of Benefit) Please refers to previous review. Table was accurately using Potential benefits. Current title might mislead reader recommendations. | This has been edited, thank you.
66 | 9 | Consider full table as previous Evidence Map. Also, although you are mention Number of included Studies to describe the evidence, most of the individuals or the sample was very small. For example, Skelly 2020 et al, suggested moderate SHORT-TERM (no more than a month) in a small sample study. Remember that this study might be use for implement project but this is not strong evidence. | The evidence table is in the appendix.
67 | 9 | The question here is in the previous review, those 4 were classified as low to very low certainty but now they were upgraded to moderate certainty? what was changed? the author did a new study? From clinical perspective, that doesn’t sound right. I dont think I will using this argument to support a stronger evidence base compared to 2018. That is the author point of view? or this is supported by the evidence? | Thank you for the comment.
68 | 9 | Correct, considering the small number of primary studies. Too small a sample may prevent the findings from being extrapolated. -- Conclusion from this review can falsely mislead that massage has strong evidence. | Thank you for the comment.
69 | 9 | This observation made the moderate certainty of evidence more weaker as its difficult to separate to sham or placebo. For those 5, you have two reviews showing beneficial effect of massage for sham/placebo and active therapies. | Thank you for the comment.
70 | 9 | Conclusions. Exercise, multidisciplinary rehabilitation, acupuncture, CBT, and mind-body practices were most consistently associated with durable slight to moderate improvements in function and pain for specific chronic pain condition -- Short term improvement in pain | Thank you for the comment.
71 | 9 | This is an important limitation as the reviewers were unable to corroborate the data and follow the conclusions of the authors. Remembers that authors might introduce a bias opinion regarding their research program if this might affect their reputation. | Thank you for the comment.
72 | 9 | This is an important topic. Grad that you add this comment in your article. Well said. | Thank you for the comment.
73 | 9 | Great point. based on your data, the moderate evidence might suggest some improvement at short term, not indeterminate or long. This is important when we are reviewing clinical practice, and outcomes in rehabilitation. | Thank you for the comment.
74 | 9 | “short-term effectiveness of massage” | This has been edited, thank you.
75 | 9 | Surprise that the following article was not included on this review, keeping in mind that was funded by VA.; Synthesizing the Strength of the Evidence of Complementary and Integrated Health Therapy for Pain. Giannitrapani . Pain Medicine 0(0) 2019 1–10.; It was conducted by your office VA Evidence Synthesis Program. | This is not a systematic review.
76 | 9 | As i mentioned before, the evidence map, use “evidence of Potential Positive Effect (not benefit)” They pointed out the size of the literature review for the one that you are consider moderate certainty, quiet small. And for massage as part of the CIH Type. really small. Acupuncture showed more evidence. This report will contradict your finding as they have massage in common. | This has been edited, thank you.
77 | 9 | The study recognized that two of the studies posted high risk of bias and a very small sample size. Only one in the US. None of the studies with control group. | Thank you for the comment.