# APPENDIX B EXCLUDED STUDIES

## Only One Primary Study About Interventions of Interest, N = 11

1 Anderson, L., ., Effectiveness of breast massage for the treatment of women with breastfeeding problems: a systematic review. JBI Database System Rev Implement Rep, 2019. 17(8): p. 1668–1694.
2 Asquini, G., ., Effectiveness of manual therapy applied to craniomandibular structures in temporomandibular disorders: A systematic review. Journal of Oral Rehabilitation, 2022. 49(4): p. 442–455.34931336
3 Crepinsek, M.A., ., Interventions for preventing mastitis after childbirth. Cochrane Database Syst Rev, 2020. 9(9): p. Cd007239.32987448
4 Fan, Z., ., The effectiveness and safety of Tuina for tension-type headache: A systematic review and meta-analysis. Complementary Therapies in Clinical Practice, 2021. 43: p. N.PAG-N.PAG.
5 Franco, J.V.A., ., Non-pharmacological interventions for treating chronic prostatitis/chronic pelvic pain syndrome: a Cochrane systematic review. BJU Int, 2019. 124(2): p. 197–208.30019814
6 Hadoush, H., ., Effectiveness of non-pharmacological rehabilitation interventions in pain management in patients with multiple sclerosis: Systematic review and meta-analysis. NeuroRehabilitation, 2022. 50(4): p. 347–365.35180138
7 Huisstede, B.M., ., Carpal Tunnel Syndrome: Effectiveness of Physical Therapy and Electrophysical Modalities. An Updated Systematic Review of Randomized Controlled Trials. Arch Phys Med Rehabil, 2018. 99(8): p. 1623–1634.e23.28942118
8 Juncker, R.B., F.M. Mirza, and J.J. Gagnier, Reduction in opioid use with perioperative non-pharmacologic analgesia in total knee arthroplasty and ACL reconstruction: a systematic review. Sicot j, 2021. 7: p. 63.34928208
9 López-Liria, R., ., Efficacy of Physiotherapy Treatment in Primary Dysmenorrhea: A Systematic Review and Meta-Analysis. Int J Environ Res Public Health, 2021. 18(15).
10 Schulze, N.B., ., Efficacy of Manual Therapy on Pain, Impact of Disease, and Quality of Life in the Treatment of Fibromyalgia: A Systematic Review. Pain Physician, 2020. 23(5): p. 461–476.32967389
11 Zakarija-Grkovic, I. and F. Stewart, Treatments for breast engorgement during lactation. Cochrane Database Syst Rev, 2020. 9(9): p. Cd006946.32944940

## Unable to Distinguish Effect for Massage Therapy from Other Included Interventions, N = 5

1 Denneny, D., ., Trigger Point Manual Therapy for the Treatment of Chronic Noncancer Pain in Adults: A Systematic Review and Meta-analysis. Archives of Physical Medicine and Rehabilitation, 2019. 100(3): p. 562–577.30025997
2 Jung, A., ., Effectiveness of physiotherapy interventions on headache intensity, frequency, duration and quality of life of patients with tension-type headache. A systematic review and network meta-analysis. Cephalalgia, 2022. 42(9): p. 944–965.35236143
3 Kamonseki, D.H., ., Effectiveness of manual therapy in patients with tension-type headache. A systematic review and meta-analysis. Disability and Rehabilitation, 2022. 44(10): p. 1780–1789.32924640
4 Qin, D., ., Acupuncture and related techniques for postoperative pain after hemorrhoidectomy: A systematic review and network meta-analysis. Eur J Integr Med, 2020. 37.
5 Wu, Q., J. Zhao, and W. Guo, Efficacy of massage therapy in improving outcomes in knee osteoarthritis: A systematic review and meta-analysis. Complement Ther Clin Pract, 2022. 46: p. 101522.34890892

## Not an Intervention of Interest, N = 3

1 Effects of Myofascial Manipulative Therapies in Chronic Pelvic Pain Syndromes: A Systematic Review and Meta-Analysis. Journal of Bodywork & Movement Therapies, 2023. 33: p. e92–e92.
2 Dal Farra, F., ., Effectiveness of Myofascial Manual Therapies in Chronic Pelvic Pain Syndrome: A Systematic Review and Meta-Analysis. Int Urogynecol J, 2022. 33(11): p. 2963–2976.35389057
3 Fuentes-Márquez, P., I. Cabrera-Martos, and M.C. Valenza, Physiotherapy interventions for patients with chronic pelvic pain: A systematic review of the literature. Physiother Theory Pract, 2019. 35(12): p. 1131–1138.29757068

## Not a Comparison of Interest, N = 2

1 Lavazza, C., ., Sham treatment effects in manual therapy trials on back pain patients: a systematic review and pairwise meta-analysis. BMJ Open, 2021. 11(5): p. e045106.
2 Mo, Z., ., Comparisons of the Effectiveness and Safety of Tuina, Acupuncture, Traction, and Chinese Herbs for Lumbar Disc Herniation: A Systematic Review and Network Meta-Analysis. Evidence-based Complementary & Alternative Medicine (eCAM), 2019: p. 1–10.

## Review Meeting Eligibility Criteria but Not Included in Evidence Map in Favor of a Better Review, N = 1

1 Chen, Z., ., The effects of myofascial release technique for patients with low back pain: A systematic review and meta-analysis. Complement Ther Med, 2021. 59: p. 102737.33984499

## Self-Delivered Therapy, N = 1

1 Cao, X., ., PFMT relevant strategies to prevent perineal trauma: a systematic review and network meta-analysis. Arch Gynecol Obstet, 2022.