# APPENDIX A SEARCH STRATEGIES

## PubMed

7/10/2018 – 12/31/2022; English Language

massag*[tiab] OR shiatsu[tiab] OR “myofascial”[tiab] OR acupressure*[tiab] OR Massage[Mesh] OR Acupressure[Mesh] OR “Myofascial Release Therapy”[Mesh]

AND

(systematic*[tiab] AND review[tiab]) OR “systematic overview*”[tiab] OR “Cochrane review*”[tiab] OR “systemic review*”[tiab] OR meta-analy*[tiab] OR metaanaly*[tiab] OR “meta analysis”[tiab] OR meta-review[tiab] OR meta-synthesis[tiab] OR “meta synthesis”[tiab] OR metasynthesis[tiab] OR “quantitative review”[tiab] OR “quantitative synthesis”[tiab] OR meta-analy*[tiab] OR (meta-analytic*[tiab] AND review[tiab]) OR meta-analysis[pt] OR “systematic review”[pt] OR “systematic review*”[tiab]

Results: 709

## CINAHL

07/2018 – 12/2023; English; Academic Journals

((TI massag* OR AB massag*) OR (TI shiatsu OR AB shiatsu) OR (TI myofascial OR AB myofascial) OR (TI acupressure* OR AB acupressure*) OR (MH “Massage+”) OR (MH Acupressure+) OR (MH “Myofascial Release”))

AND

((TI systematic* OR AB systematic*) AND (TI review OR AB review)) OR (TI “systematic overview*” OR AB “systematic overview*”) OR (TI “Cochrane review*” OR AB “Cochrane review*”) OR (TI “systemic review*” OR AB “systemic review*”) OR (TI meta-analy* OR AB meta-analy*) OR (TI metaanaly* OR AB metaanaly*) OR (TI “meta analysis” OR AB “meta analysis”) OR (TI meta-review OR AB meta-review) OR (TI meta-synthesis OR AB meta-synthesis) OR (TI “meta synthesis” OR AB “meta synthesis”) OR (TI metasynthesis OR AB metasynthesis) OR (TI “quantitative review” OR AB “quantitative review”) OR (TI “quantitative synthesis” OR AB “quantitative synthesis”) OR ((TI meta-analytic* OR AB meta-analytic*) AND (TI review OR AB review)) OR (TI “systematic review*” OR AB “systematic review*”) OR (MH “Systematic Review”)

Results: 555

## Cochrane Database of Systematic Reviews

Filters: 07/2018 – 12/2023; Excluding Trials

((massag* OR shiatsu OR myofascial OR acupressure*):ti,ab OR [mh Massage] OR [mh Acupressure] OR [mh “Myofascial Release Therapy”])

Results: 36

## Web of Science

Filters: 2018-2023; English

(TS=massag* OR TS=shiatsu OR TS=myofascial OR TS=acupressure*)

AND

((TI=systematic* OR AB=systematic*) AND (TI=review OR AB=review)) OR (TI=“systematic overview*” OR AB=“systematic overview*”) OR (TI=“Cochrane review*” OR AB=“Cochrane review*”) OR (TI=“systemic review*” OR AB=“systemic review*”) OR (TI=meta-analy* OR AB=meta-analy*) OR (TI=metaanaly* OR AB=metaanaly*) OR (TI=“meta analysis” OR AB=“meta analysis”) OR (TI=meta-review OR AB=meta-review) OR (TI=meta-synthesis OR AB=meta-synthesis) OR (TI=“meta synthesis” OR AB=“meta synthesis”) OR (TI=metasynthesis OR AB=metasynthesis) OR (TI=“quantitative review” OR AB=“quantitative review”) OR (TI=“quantitative synthesis” OR AB=“quantitative synthesis”) OR ((TI=meta-analytic* OR AB=meta-analytic*) AND (TI=review OR AB=review)) OR (TI=“systematic review*” OR AB=“systematic review*”)

Results: 960

## AMED

Filters: 07/2018 – 12/2022; English; Academic Journals

((TI massag* OR AB massag*) OR (TI shiatsu OR AB shiatsu) OR (TI myofascial OR AB myofascial) OR (TI acupressure* OR AB acupressure*) OR (DE “MASSAGE”) OR (DE “ACUPRESSURE”))

AND

((TI systematic* OR AB systematic*) AND (TI review OR AB review)) OR (TI “systematic overview*” OR AB “systematic overview*”) OR (TI “Cochrane review*” OR AB “Cochrane review*”) OR (TI “systemic review*” OR AB “systemic review*”) OR (TI meta-analy* OR AB meta-analy*) OR (TI metaanaly* OR AB metaanaly*) OR (TI “meta analysis” OR AB “meta analysis”) OR (TI meta-review OR AB meta-review) OR (TI meta-synthesis OR AB meta-synthesis) OR (TI “meta synthesis” OR AB “meta synthesis”) OR (TI metasynthesis OR AB metasynthesis) OR (TI “quantitative review” OR AB “quantitative review”) OR (TI “quantitative synthesis” OR AB “quantitative synthesis”) OR ((TI meta-analytic* OR AB meta-analytic*) AND (TI review OR AB review)) OR (TI “systematic review*” OR AB “systematic review*”)

Results: 960