# ABBREVIATIONS TABLE

Abbreviation: Definition
AHRQ: Agency for Healthcare Research & Quality
CIH: Complementary and integrative health
EPC: Evidence-based Practice Center
ESP: Evidence Synthesis Program
GRADE: Grading of Recommendations, Assessment, Development and Evaluations
MFR: Myofascial release
VA: Department of Veterans Affairs
VERDICT: Veterans Response to Dosage in Chiropractic Therapy
VHA: Veterans Health Administration