# REFERENCES

1 Watts NB. Osteoporosis in men. Endocr Pract. 2013;19(5):834–8.23757624
2 Center JR, Nguyen TV, Schneider D, . Mortality after all major types of osteoporotic fracture in men and women: an observational study. Lancet. 1999;353(9156):878–82.10093980
3 Cosman F, de Beur SJ, LeBoff MS, . Clinician’s Guide to Prevention and Treatment of Osteoporosis. Osteoporos Int. 2014;25(10):2359–81.25182228
4 Lewiecki EM, Gordon CM, Baim S, . International Society for Clinical Densitometry 2007 Adult and Pediatric Official Positions. Bone. 2008;43(6):1115–21.18793764
5 Watts NB, Adler RA, Bilezikian JP, . Osteoporosis in men: an Endocrine Society clinical practice guideline. J Clin Endocrinol Metab. 2012;97(6):1802–22.22675062
6 Curry SJ, Krist AH, Owens DK, . Screening for Osteoporosis to Prevent Fractures: US Preventive Services Task Force Recommendation Statement. JAMA. 2018;319(24):2521–2531.29946735
7 Jain S, Bilori B, Gupta A, . Are Men at High Risk for Osteoporosis Underscreened? A Quality Improvement Project. Perm J. 2016;20(1):60–64.26824964
8 Kanis JA, Melton LJ, 3rd, Christiansen C, . The diagnosis of osteoporosis. J Bone Miner Res. 1994;9(8):1137–41.7976495
9 Compston J, Cooper A, Cooper C, . UK clinical guideline for the prevention and treatment of osteoporosis. Arch Osteoporos. 2017;12(1):43.28425085
10 LaFleur J, Rillamas-Sun E, Colon-Emeric CS, . Fracture Rates and Bone Density Among Postmenopausal Veteran and Non-Veteran Women From the Women’s Health Initiative. Gerontologist. 2016;56 Suppl 1:S78–90.26768394
11 Nahm ES, Charters K, Yoo E, . Osteoporosis Preventive Practice Between Veteran and Nonveteran Older Adults: Findings From Patient-Reported Data. Orthop Nurs. 2016;35(6):401–410.27851678
12 Moher D, Liberati A, Tetzlaff J, . Preferred reporting items for systematic reviews and meta-analyses: the PRISMA statement. Ann Intern Med. 2009;151(4):264–9, W64.19622511
13 Cochrane EPOC. Suggested risk of bias criteria for EPOC reviews. EPOC Resources for review authors, 2017. Available at: http://epoc.cochrane.org/resources/epoc-resources-review-authors. Accessed September 21, 2020.
14 Watts NB, Leslie WD, Foldes AJ, . 2013 International Society for Clinical Densitometry Position Development Conference: Task Force on Normative Databases. J Clin Densitom. 2013;16(4):472–81.24076161
15 Evidence Partners Inc. DistillerAI website. Available at: https://www.evidencepartners.com/distiller-ai/. Accessed September 21, 2020.
16 Agency for Healthcare Research and Quality. Assessing the Accuracy of Machine-Assisted Abstract Screening With DistillerAI: A User Study. AHRQ Publication No. 19(20)-EHC026-EF. 2019.
17 Lewiecki EM, Bouchonville MF, 2nd, Chafey DH, . Bone Health ECHO: telementoring to improve osteoporosis care. Women’s health (London, England). 2016;12(1):79–81.
18 Hajian-Tilaki K. Receiver Operating Characteristic (ROC) Curve Analysis for Medical Diagnostic Test Evaluation. Caspian journal of internal medicine. 2013;4(2):627–635.24009950
19 Mandrekar JN. Receiver Operating Characteristic Curve in Diagnostic Test Assessment. J Thorac Oncol. 2010;5(9):1315–1316.20736804
20 Whiting PF, Rutjes AW, Westwood ME, . QUADAS-2: a revised tool for the quality assessment of diagnostic accuracy studies. Ann Intern Med. 2011;155(8):529–36.22007046
21 Evidence Partners. Methods Commentary: Risk of Bias in Cohort Studies. Available at: https://www.evidencepartners.com/resources/methodological-resources/risk-of-bias-in-cohort-studies/. Accessed September 21, 2020.
22 Veroniki AA, Jackson D, Bender R, . Methods to calculate uncertainty in the estimated overall effect size from a random-effects meta-analysis. Res Synth Methods. 2019;10(1):23–43.30129707
23 Hultcrantz M, Rind D, Akl EA, . The GRADE Working Group clarifies the construct of certainty of evidence. J Clin Epidemiol. 2017;87:4–13.28529184
24 Kanis JA, Harvey NC, Johansson H, . Overview of Fracture Prediction Tools. J Clin Densitom. 2017;20(3):444–450.28716500
25 Ettinger B, Ensrud KE, Blackwell T, . Performance of FRAX in a cohort of community-dwelling, ambulatory older men: the Osteoporotic Fractures in Men (MrOS) study. Osteoporos Int. 2013;24(4):1185–93.23179575
26 Yin MT, Shiau S, Rimland D, . Fracture Prediction With Modified-FRAX in Older HIV-Infected and Uninfected Men. J Acquir Immune Defic Syndr. 2016;72(5):513–20.27003493
27 Cass AR, Shepherd AJ, Asirot R, . Comparison of the Male Osteoporosis Risk Estimation Score (MORES) With FRAX in Identifying Men at Risk for Osteoporosis. Ann Fam Med. 2016;14(4):365–9.27401426
28 Williams ST, Lawrence PT, Miller KL, . A comparison of electronic and manual fracture risk assessment tools in screening elderly male US veterans at risk for osteoporosis. Osteoporos Int. 2017;28(11):3107–3111.28756457
29 Diem SJ, Peters KW, Gourlay ML, . Screening for Osteoporosis in Older Men: Operating Characteristics of Proposed Strategies for Selecting Men for BMD Testing. J Gen Intern Med. 2017;32(11):1235–1241.28815485
30 Gourlay ML, Ritter VS, Fine JP, . Comparison of fracture risk assessment tools in older men without prior hip or spine fracture: the MrOS study. Arch Osteoporos. 2017;12(1):91.29052793
31 Hamdy RC, Seier E, Whalen K, . FRAX calculated without BMD does not correctly identify Caucasian men with densitometric evidence of osteoporosis. Osteoporos Int. 2018;29(4):947–952.29397409
32 Hippisley-Cox J, Coupland C. Predicting risk of osteoporotic fracture in men and women in England and Wales: prospective derivation and validation of QFractureScores. BMJ. 2009;339:b4229.19926696
33 Friis-Holmberg T, Rubin KH, Brixen K, . Fracture risk prediction using phalangeal bone mineral density or FRAX((R))?-A Danish cohort study on men and women. J Clin Densitom. 2014;17(1):7–15.23623379
34 Short CE, Shaw SG, Fisher MJ, . Comparison of peripheral forearm DXA and clinical risk factor screening using FRAX(R) to assess the risk of HIV-associated low bone mass: a cross-sectional study. Arch Osteoporos. 2014;9:181.24847675
35 Hoff M, Meyer HE, Skurtveit S, . Validation of FRAX and the impact of self-reported falls among elderly in a general population: the HUNT study, Norway. Osteoporos Int. 2017;28(10):2935–2944.28668994
36 Marques A, Lucas R, Simoes E, . Do we need bone mineral density to estimate osteoporotic fracture risk? A 10-year prospective multicentre validation study. RMD Open. 2017;3(2):e000509.29018567
37 Nakatoh S, Takemaru Y. Application of the fracture risk assessment tool (FRAX((R))) and determination of suitable cut-off values during primary screening in specific health check-ups in Japan. J Bone Miner Metab. 2013;31(6):674–80.23543192
38 Kim JW, Koh JM, Park JH, . Validation of FRAX without BMD: an age-related analysis of the Fifth Korean National Health and Nutrition Examination Survey (KNHANES V-1, 2010). Bone. 2015;75:27–31.25697083
39 Jang EJ, Lee YK, Choi HJ, . Osteoporotic Fracture Risk Assessment Using Bone Mineral Density in Korean: A Community-based Cohort Study. J Bone Metab. 2016;23(1):34–9.26981519
40 Dagan N, Cohen-Stavi C, Leventer-Roberts M, . External validation and comparison of three prediction tools for risk of osteoporotic fractures using data from population based electronic health records: retrospective cohort study. BMJ. 2017;356:i6755.28104610
41 Yang S, Leslie WD, Morin SN, . Administrative healthcare data applied to fracture risk assessment. Osteoporos Int. 2019;30(3):565–571.30554259
42 Leslie WD, Morin S, Lix LM, . Fracture risk assessment without bone density measurement in routine clinical practice. Osteoporos Int. 2012;23(1):75–85.21850546
43 Holloway-Kew KL, Zhang Y, Betson AG, . How well do the FRAX (Australia) and Garvan calculators predict incident fractures? Data from the Geelong Osteoporosis Study. Osteoporos Int. 2019;30(10):2129–2139.31317250
44 Hosmer DW, Lemeshow S, Sturdivant RX. Applied logistic regression. Third edition / ed Hoboken, New Jersey: Wiley; 2013 Wiley series in probability and statistics).
45 Leslie WD, Johansson H, McCloskey EV, . Comparison of Methods for Improving Fracture Risk Assessment in Diabetes: The Manitoba BMD Registry. J Bone Miner Res. 2018;33(11):1923–1930.29953670
46 Kanis JA, Johansson H, Oden A, . Guidance for the adjustment of FRAX according to the dose of glucocorticoids. Osteoporos Int. 2011;22(3):809–816.21229233
47 Leslie WD, Lix LM, Johansson H, . Spine-hip discordance and fracture risk assessment: a physician-friendly FRAX enhancement. Osteoporos Int. 2011;22(3):839–47.20959961
48 Adler RA, Hastings FW, Petkov VI. Treatment thresholds for osteoporosis in men on androgen deprivation therapy: T-score versus FRAX. Osteoporos Int. 2010;21(4):647–53.19533207
49 Subramaniam S, Ima-Nirwana S, Chin KY. Performance of osteoporosis self-assessment tool (OST) in predicting osteoporosis—a review. Int J Environ Res Public Health. 2018;15(7).
50 Machado P, Coutinho M, da Silva JA. Selecting men for bone densitometry: performance of osteoporosis risk assessment tools in Portuguese men. Osteoporos Int. 2010;21(6):977–83.19727909
51 Sinnott B, Kukreja S, Barengolts E. Utility of screening tools for the prediction of low bone mass in African American men. Osteoporos Int. 2006;17(5):684–92.16523248
52 Skedros JG, Sybrowsky CL, Stoddard GJ. The osteoporosis self-assessment screening tool: a useful tool for the orthopaedic surgeon. J Bone Joint Surg Am. 2007;89(4):765–72.17403798
53 Richards JS, Lazzari AA, Teves Qualler DA, . Validation of the osteoporosis self-assessment tool in US male veterans. J Clin Densitom. 2014;17(1):32–7.23489972
54 Adler RA, Tran MT, Petkov VI. Performance of the Osteoporosis Self-assessment Screening Tool for osteoporosis in American men. Mayo Clin Proc. 2003;78(6):723–7.12934782
55 Oh SM, Song BM, Nam BH, . Development and Validation of Osteoporosis Risk-Assessment Model for Korean Men. Yonsei Med J. 2016;57(1):187–96.26632400
56 Richards JS, Peng J, Amdur RL, . Dual-energy X-ray absorptiometry and evaluation of the osteoporosis self-assessment tool in men with rheumatoid arthritis. J Clin Densitom. 2009;12(4):434–40.19775920
57 Hippisley-Cox J, Coupland C. Derivation and validation of updated QFracture algorithm to predict risk of osteoporotic fracture in primary care in the United Kingdom: prospective open cohort study. BMJ. 2012;344:e3427.22619194
58 Collins GS, Mallett S, Altman DG. Predicting risk of osteoporotic and hip fracture in the United Kingdom: prospective independent and external validation of QFractureScores. BMJ. 2011;342:d3651.21697214
59 Shepherd AJ, Cass AR, Carlson CA, . Development and internal validation of the male osteoporosis risk estimation score. Ann Fam Med. 2007;5(6):540–6.18025492
60 Shepherd AJ, Cass AR, Ray L. Determining risk of vertebral osteoporosis in men: validation of the male osteoporosis risk estimation score. J Am Board Fam Med. 2010;23(2):186–94.20207929
61 Cass AR, Shepherd AJ. Validation of the Male Osteoporosis Risk Estimation Score (MORES) in a primary care setting. J Am Board Fam Med. 2013;26(4):436–44.23833159
62 Garvan Institute of Medical Research. Bone Fracture Risk Calculator. 2021.
63 Nguyen ND, Frost SA, Center JR, . Development of prognostic nomograms for individualizing 5-year and 10-year fracture risks. Osteoporos Int. 2008;19(10):1431–1444.18324342
64 Francesco L, Elisa B, Raffaella M, . Assessing Risk of Osteoporotic Fractures in Primary Care: Development and Validation of the FRA-HS Algorithm. Calcif Tissue Int. 2017;100(6):537–549.28160026
65 Hayashi S, Hashimoto S, Kanzaki N, . Stem anteversion affects periprosthetic bone mineral density after total hip arthroplasty. Hip Int. 2016;26(3):260–4.27102558
66 Ettinger B, Liu H, Blackwell T, . Validation of FRC, a fracture risk assessment tool, in a cohort of older men: the Osteoporotic Fractures in Men (MrOS) Study. J Clin Densitom. 2012;15(3):334–42.22445858
67 Zimering MB, Shin JJ, Shah J, . Validation of a novel risk estimation tool for predicting low bone density in Caucasian and African American men veterans. J Clin Densitom. 2007;10(3):289–97.17459748
68 Kim HY, Jang EJ, Park B, . Development of a Korean Fracture Risk Score (KFRS) for Predicting Osteoporotic Fracture Risk: Analysis of Data from the Korean National Health Insurance Service. PLoS One. 2016;11(7):e0158918.27399597
69 Munigala S, Agarwal B, Gelrud A, . Chronic Pancreatitis and Fracture: A Retrospective, Population-Based Veterans Administration Study. Pancreas. 2016;45(3):355–61.26199986
70 Papaleontiou M, Banerjee M, Reyes-Gastelum D, . Risk of Osteoporosis and Fractures in Patients with Thyroid Cancer: A Case-Control Study in U.S. Veterans. Oncologist. 2019.
71 Hsieh E, Shiau S, Nolan O, . Increased Fragility Fracture Rates in Older Men with Osteomyelitis. Clin Infect Dis. 2019.
72 Weaver J, Kawsky J, Corboy A. Antipsychotic use and fracture risk: An evaluation of incidence at a Veterans Affairs medical center. Ment Health Clin. 2019;9(1):6–11.30627497
73 Hall RK, Sloane R, Pieper C, . Competing Risks of Fracture and Death in Older Adults with Chronic Kidney Disease. J Am Geriatr Soc. 2018;66(3):532–538.29319880
74 Khan N, Abbas AM, Almukhtar RM, . Prevalence and predictors of low bone mineral density in males with ulcerative colitis. J Clin Endocrinol Metab. 2013;98(6):2368–75.23596137
75 Womack JA, Goulet JL, Gibert C, . Physiologic frailty and fragility fracture in HIV-infected male veterans. Clin Infect Dis. 2013;56(10):1498–504.23378285
76 Hain RE, Hoyt RE, Moore JL, . Potential association of posttraumatic stress disorder and decreased bone mineral density in repatriated prisoners of war. Mil Med. 2011;176(3):270–5.21456352
77 Womack JA, Goulet JL, Gibert C, . Increased risk of fragility fractures among HIV infected compared to uninfected male veterans. PLoS One. 2011;6(2):e17217.21359191
78 Akhter N, Sinnott B, Mahmood K, . Effects of vitamin D insufficiency on bone mineral density in African American men. Osteoporos Int. 2009;20(5):745–750.18820989
79 Shahani L, Breaux K, Lin M, . Veterans Aging Cohort Study Index as a Marker of Bone Disease in HIV-Infected Patients. AIDS Res Hum Retroviruses. 2019;35(11–12):1143–1147.31379187
80 Pettersson U, Nilsson M, Sundh V, . Physical activity is the strongest predictor of calcaneal peak bone mass in young Swedish men. Osteoporos Int. 2010;21(3):447–455.19533209
81 Alswat KA. Gender Disparities in Osteoporosis. J Clin Med Res. 2017;9(5):382–387.28392857
82 Schuit SC, van der Klift M, Weel AE, . Fracture incidence and association with bone mineral density in elderly men and women: the Rotterdam Study. Bone. 2004;34(1):195–202.14751578
83 Trajanoska K, Schoufour JD, de Jonge EAL, . Fracture incidence and secular trends between 1989 and 2013 in a population based cohort: The Rotterdam Study. Bone. 2018;114:116–124.29885926
84 Tate JP, Justice AC. Change in a prognostic index for survival in HIV infection after one year on cART by level of adherence. 48th Annual Meeting of the Infectious Diseases Society of America. Vancouver, British Columbia, Canada,; 2010.
85 Akgun KM, Pisani MA, Fried TR, . Risk Factors for Medical Intensive Care Unit Admission in HIV Infected Veterans. American Thoracic Society International Conference. New Orleans, LA; 2010.
86 Oursler KK, Goulet JL, Crystal S, . Association of age and comorbidity with physical function in HIV-infected and uninfected patients: results from the Veterans Aging Cohort Study. AIDS Patient Care STDS. 2011;25(1):13–20.21214375
87 Yadav D, Dhir R. HOW ACCURATE ARE ICD-9 CODES FOR ACUTE (AP) AND CHRONIC (CP) PANCREATITIS?-A LARGE VA HOSPITAL EXPERIENCE. Pancreas. 2006;33(4).
88 Institute of Medicine. The Health of Former Prisoners of War : Results from the Medical Examination Survey of Former POWs of World War II and the Korean Conflict. The National Academies Press; 1992.
89 Fujiyama K, Kiriyama T, Ito M, . Suppressive doses of thyroxine do not accelerate age-related bone loss in late postmenopausal women. Thyroid. 1995;5(1):13–7.7787427
90 Wang LY, Smith AW, Palmer FL, . Thyrotropin suppression increases the risk of osteoporosis without decreasing recurrence in ATA low- and intermediate-risk patients with differentiated thyroid carcinoma. Thyroid. 2015;25(3):300–7.25386760
91 Szafors P, Che H, Barnetche T, . Risk of fracture and low bone mineral density in adults with inflammatory bowel diseases. A systematic literature review with meta-analysis. Osteoporos Int. 2018;29(11):2389–2397.29909470
92 Dolan BM, Yialamas MA, McMahon GT. A Randomized Educational Intervention Trial to Determine the Effect of Online Education on the Quality of Resident-Delivered Care. J Grad Med Educ. 2015;7(3):376–81.26457142
93 Solomon DH, Katz JN, Finkelstein JS, . Osteoporosis improvement: a large-scale randomized controlled trial of patient and primary care physician education. J Bone Miner Res. 2007;22(11):1808–15.17645403
94 Curtis JR, Westfall AO, Allison J, . Challenges in improving the quality of osteoporosis care for long-term glucocorticoid users: a prospective randomized trial. Arch Intern Med. 2007;167(6):591–6.17389291
95 Solomon DH, Katz JN, La Tourette AM, . Multifaceted intervention to improve rheumatologists’ management of glucocorticoid-induced osteoporosis: a randomized controlled trial. Arthritis Rheum. 2004;51(3):383–7.15188323
96 Pazirandeh M. Does patient partnership in continuing medical education (CME) improve the outcome in osteoporosis management? J Contin Educ Health Prof. 2002;22(3):142–51.12227236
97 Alibhai SMH, Breunis H, Timilshina N, . Improving bone health in men with prostate cancer receiving androgen deprivation therapy: Results of a randomized phase 2 trial. Cancer. 2018;124(6):1132–1140.29211305
98 Solomon DH, Polinski JM, Stedman M, . Improving care of patients at-risk for osteoporosis: a randomized controlled trial. J Gen Intern Med. 2007;22(3):362–7.
99 El-Kareh RE, Gandhi TK, Poon EG, . Actionable reminders did not improve performance over passive reminders for overdue tests in the primary care setting. J Am Med Inform Assoc. 2011;18(2):160–3.21278102
100 Levy BT, Hartz A, Woodworth G, . Interventions to improving osteoporosis screening: an Iowa Research Network (IRENE) study. J Am Board Fam Med. 2009;22(4):360–7.19587249
101 Loo TS, Davis RB, Lipsitz LA, . Electronic medical record reminders and panel management to improve primary care of elderly patients. Arch Intern Med. 2011;171(17):1552–8.21949163
102 Lafata JE, Kolk D, Peterson EL, . Improving osteoporosis screening: results from a randomized cluster trial. J Gen Intern Med. 2007;22(3):346–51.17356966
103 Kastner M, Sawka AM, Hamid J, . A knowledge translation tool improved osteoporosis disease management in primary care: an interrupted time series analysis. Implement Sci. 2014;9:109.25252858
104 Denberg TD, Myers BA, Lin CT, . An outreach intervention increases bone densitometry testing in older women. J Am Geriatr Soc. 2009;57(2):341–7.19207149
105 Heyworth L, Kleinman K, Oddleifson S, . Comparison of interactive voice response, patient mailing, and mailed registry to encourage screening for osteoporosis: a randomized controlled trial. Osteoporos Int. 2014;25(5):1519–26.24566584
106 Yuksel N, Majumdar SR, Biggs C, . Community pharmacist-initiated screening program for osteoporosis: randomized controlled trial. Osteoporos Int. 2010;21(3):391–8.19499272
107 Rubin KH, Rothmann MJ, Holmberg T, . Effectiveness of a two-step population-based osteoporosis screening program using FRAX: the randomized Risk-stratified Osteoporosis Strategy Evaluation (ROSE) study. Osteoporos Int. 2018;29(3):567–578.
108 Warriner AH, Outman RC, Kitchin E, . A randomized trial of a mailed intervention and self-scheduling to improve osteoporosis screening in postmenopausal women. J Bone Miner Res. 2012;27(12):2603–10.22836812
109 Warriner AH, Outman RC, Feldstein AC, . Effect of self-referral on bone mineral density testing and osteoporosis treatment. Med Care. 2014;52(8):743–50.24984211
110 Ayoub WT, Newman ED, Blosky MA, . Improving detection and treatment of osteoporosis: redesigning care using the electronic medical record and shared medical appointments. Osteoporos Int. 2009;20(1):37–42.18493699
111 Garton MJ, Torgerson DJ, Donaldson C, . Recruitment methods for screening programmes: trial of a new method within a regional osteoporosis study. BMJ. 1992;305(6845):82–4.1638251
112 Shepstone L, Lenaghan E, Cooper C, . Screening in the community to reduce fractures in older women (SCOOP): a randomised controlled trial. Lancet. 2018;391(10122):741–747.29254858
113 Shekelle P, Munjas B, Liu H, . (Department of Veterans Affairs). Screening Men for Osteoporosis: Who & How. 2007.
114 Allon R, Levy Y, Lavi I, . How to Best Predict Fragility Fractures: An Update and Systematic Review. Isr Med Assoc J. 2018;20(12):773–779.30550009
115 Cruz AS, Lins HC, Medeiros RVA, . Artificial intelligence on the identification of risk groups for osteoporosis, a general review. Biomed Eng Online. 2018;17(1):12.29378578
116 Little EA, Eccles MP. A systematic review of the effectiveness of interventions to improve post-fracture investigation and management of patients at risk of osteoporosis. Implement Sci. 2010;5:80.20969769
117 Laliberte MC, Perreault S, Jouini G, . Effectiveness of interventions to improve the detection and treatment of osteoporosis in primary care settings: a systematic review and meta-analysis. Osteoporos Int. 2011;22(11):2743–68.21336493
118 Tzortziou Brown V, Underwood M, Mohamed N, . Professional interventions for general practitioners on the management of musculoskeletal conditions. Cochrane Database Syst Rev. 2016(5):Cd007495.27150167
119 Morfeld JC, Vennedey V, Muller D, . Patient education in osteoporosis prevention: a systematic review focusing on methodological quality of randomised controlled trials. Osteoporos Int. 2017;28(6):1779–1803.28236127
120 Hillier TA, Cauley JA, Rizzo JH, . WHO absolute fracture risk models (FRAX): do clinical risk factors improve fracture prediction in older women without osteoporosis? J Bone Miner Res. 2011;26(8):1774–82.21351144
121 Adam GP, Springs S, Trikalinos T, . Does information from ClinicalTrials.gov increase transparency and reduce bias? Results from a five-report case series. Syst Rev. 2018;7(1):59.29661214
122 Robinson KA, Saldanha IJ, McKoy NA. Development of a framework to identify research gaps from systematic reviews. J Clin Epidemiol. 2011;64(12):1325–30.21937195
123 Rubin KH, Holmberg T, Rothmann MJ, . The risk-stratified osteoporosis strategy evaluation study (ROSE): a randomized prospective population-based study. Design and baseline characteristics. Calcif Tissue Int. 2015;96(2):167–79.25578146
124 Carey JA-O, Yang L, Erjiang E, . Vertebral Fractures in Ireland: A Sub-analysis of the DXA HIP Project. (1432-0827 (Electronic)).