# ACKNOWLEDGMENTS

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors are grateful to Dr. Stacy Lavin and Liz Wing for editorial and citation management support, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Leonard Pogach, MD
  Chief Consultant
  Specialty Care Services
- Robert Adler, MD
  Chair
  Osteoporosis Field Advisory Committee
- Grant Cannon, MD
  Chair
  Osteoporosis Field Advisory Committee

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Cathleen Colon-Emeric, MD
  Associate Director-Clinician, GRECC
  Durham VA Health Care System
  Durham, NC
- Karen Hansen, MD, MS
  Associate professor
  University of Wisconsin
  Madison, WI
- Anne Schafer, MD
  Staff Physician
  San Francisco VA Health Care System
  San Francisco, CA

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.