# SUMMARY AND DISCUSSION

Primary prevention of osteoporosis is largely sought through screening to identify those at highest risk of fracture-related morbidity. While screening women aged 65 and older for osteoporosis is standard clinical practice, and is associated with fracture risk reduction,^112^ there is uncertainty about the role of screening among men.^3^ Further, there is significant uncertainty about how to screen men when screening is determined to be warranted. Thus, fracture risk-assessment tools, such as the FRAX^®^ risk assessment tool, have been developed to identify those who are at high risk for osteoporosis and fracture. Screening by fracture risk tool first, rather than by DXA, has been proposed as an alternate means to identify those at increased risk for fracture.^9^

The issue of screening for osteoporosis among men is particularly pertinent to the VHA. Veterans are at higher risk for osteoporotic fractures than non-Veterans.^10^

However, continued research is needed to support optimal choice and use of clinical risk assessment tools specific to male Veterans, including head-to-head comparisons of specific tools to help guide clinical decision-making. From a clinical perspective, risk assessment tools like the OST, Garvan, and MORES may be more likely to be implemented in the clinical setting if the variables are easily accessible via the EHR and still report moderate to excellent discrimination. Given that the VHA is an integrated health system, it is particularly well suited to conducting research on system-level interventions to improve screening for osteoporosis and fracture risk.

## SUMMARY OF EVIDENCE BY KEY QUESTION

### Key Question 1 Summary

KQ 1 Among males not identified by a history of low-trauma fracture, is there a clinical risk tool (eg, FRAX^®^) that identifies patients at highest risk of osteoporosis or major osteoporotic fracture?

We sought to synthesize the evidence on clinical risk assessment tools that identify men at highest risk of osteoporosis or major osteoporotic fracture. Overall, we identified 37 studies that met our inclusion criteria encompassing 18 different clinical risk tools. There were 19 studies that assessed the FRAX risk assessment tool or a modified version of the FRAX risk assessment tool. Tools varied in their complexity, ranging from only 2 risk factors (ie, OST) to more than 20 risk factors (ie, QFracture). Nine studies assessed the OST/OSTA. QFracture (2 different versions) was used in 5 studies. Four studies evaluated the MORES risk tool. The Garvan tool was assessed in 4 studies. The remaining tools were each evaluated in only 1 study. The FRAX tool was the only tool assessed with all 3 outcomes: MOF, hip fracture, and osteoporosis. While we aimed to synthesize all relevant risk assessment metrics, sensitivity and specificity were underreported across studies, and included studies often did not report the necessary elements to compute these outcomes. Thus, we relied on the AUC, as it was the most commonly reported outcome across included studies.

Overall, we found little evidence that directly compared risk assessment tools within the same population of men. Among the risk assessment tools assessed, the OST has good discrimination in predicting osteoporosis by DXA and had two, easily obtainable variables (AUC ranging from 0.632 to 0.890). The other 2 tools identified that predicted risk of osteoporosis (FRAX, MORES) had high heterogeneity in AUC, ranging from poor to excellent discrimination (AUC ranging from 0.596 to 0.870). Tools such as FRAX, QFracture, and Garvan display poor to excellent discrimination in predicting hip fracture and MOF (0.609 to 0.930 for hip fracture; 0.618 to 0.810 for MOF). Yet, among men not identified via prior fracture, the FRAX risk assessment tool has better discrimination in predicting hip fracture than MOF and osteoporosis diagnosis. It is worth noting that several studies examining osteoporosis as an outcome in men used a male normative database to define low BMD, whereas FRAX uses the female normative database. This may have altered the discrimination of FRAX to identify osteoporosis in men. Limited evidence was identified for use of FRAX in special populations such as individuals with HIV and those on androgen deprivation therapy (ADT), but it was generally found to perform worse among these groups. Less common tools were reported by 9 studies and had variable discriminatory ability.

Risk of developing osteoporosis, hip fracture, or MOF were deemed the outcomes critical to decision-making. Thus, these are the outcomes for which we conducted certainty of evidence (COE) ratings. These COE judgments reflect the degree of confidence we have in our summary findings. For each outcome of interest, we present the COE organized first by outcome modeled (ie, osteoporosis, hip fracture, MOF) for each of the major risk assessment tools, and then by sensitivity, specificity, and AUC. COE ratings are summarized below, with supporting information provided in Table 14.

- We found low to very low COE to support that OST, FRAX, and MORES identifies men at high risk of osteoporosis across all 3 risk assessment metrics of sensitivity, specificity, and AUC.
- We found low to very low COE to support that FRAX identifies men at high risk of hip fracture across all 3 risk assessment metrics of sensitivity, specificity, and AUC. We found the Garvan too was low COE for sensitivity and specificity but moderate COE using the AUC measure. QFracture was also judged to be low COE for hip fracture identification among men as assessed by AUC alone.
- We found very low COE that FRAX identifies men at risk for MOF as assessed by AUC only. For QFracture, we found moderate COE that this risk assessment tool identifies men at high risk of MOF.
- Of the included studies, 50% were judged to be at high risk of bias using QUADAS-2.

Table 14 Certainty of Evidence for Main Outcomes of Osteoporosis Risk Assessment Tools

Outcome | Number of Studies (N) | Findings | Certainty of Evidence (Rationale)
OSTEOPOROSIS
OST
Sensitivity | 8 studies; (6,805 participants) | Sensitivity range: 0.688 to 0.930 (range of 95% CI 0.588 to 0.997) | Low certainty that OST identifies men at high risk of osteoporosis; (rated down for very serious risk of bias)
Sensitivity | 1 study; (282 patients with rheumatoid arthritis) | 0.64 (95% CI NR) | Low certainty that OST identifies men at high risk of osteoporosis; (rated down for very serious risk of bias)
Specificity | 8 studies; (6,805 participants) | Specificity range: 0.336 to 0.660 (range of 95% CI 0.292 to 0.735) | Very low certainty that OST identifies men at high risk of osteoporosis; (rated down for very serious risk of bias, indirectness, inconsistency)
Specificity | 1 study; (282 patients with rheumatoid arthritis) | 0.54 (95% CI NR) | Very low certainty that OST identifies men at high risk of osteoporosis; (rated down for very serious risk of bias, indirectness, inconsistency)
AUC | 8 studies; (6,805 participants) | AUC range: 0.632 to 0.890 (range of 95% CI 0.535 to 1.030) | Low certainty that OST identifies men at high risk of osteoporosis; (rated down for very serious risk of bias)
FRAX
Sensitivity | 3 studies; (6,267 participants) | Sensitivity range: 0.390 to 0.766 (range of 95% CI 0.270 to 0.825) | Very Low certainty that FRAX identifies men at high risk of osteoporosis; (rated down for very serious risk of bias, very serious inconsistency, and very serious imprecision)
Sensitivity | 1 study; (400 participants) | 58.3 men 74 or younger; 63.8 men 75 or older | Very Low certainty that FRAX identifies men at high risk of osteoporosis; (rated down for very serious risk of bias, very serious inconsistency, and very serious imprecision)
Specificity | 3 studies; (6,267 participants) | Specificity range: 0.427 to 0.890 (range of 95% CI 0.384 to 0.910) | Very low certainty that FRAX identifies men at high risk of osteoporosis; (rated down for very serious risk of bias, serious indirectness, very serious inconsistency, and very serious imprecision)
Specificity | 1 study; (400 participants) | 58.4 (95% CI NR); Men 74 or younger; 65.8 (95% CI NR); Men 75 or older | Very low certainty that FRAX identifies men at high risk of osteoporosis; (rated down for very serious risk of bias, serious indirectness, very serious inconsistency, and very serious imprecision)
AUC | 3 studies; (6,267 participants) | AUC range 0.596 to 0.790 (range of 95% CI 0.547 to 0.840) | Very low certainty that FRAX identifies men at high risk of osteoporosis; (rated down for very serious risk of bias, very serious inconsistency, and very serious imprecision)
AUC | 1 study; (400 participants) | 0.63 (95% CI 0.49 to 0.77); Men 74 or younger; 0.67 (95% CI 0.59 to 0.75); Men 75 or older | Very low certainty that FRAX identifies men at high risk of osteoporosis; (rated down for very serious risk of bias, very serious inconsistency, and very serious imprecision)
MORES
Sensitivity | 4 studies; (6,285 participants) | Sensitivity range 0.655 to 0.960 (range of 95% CI 0.520 to 0.990) | Very low certainty that MORES identifies men at high risk of osteoporosis; (rated down for serious risk of bias, serious inconsistency, very serious imprecision)
Specificity | 4 studies; (6,285 participants) | Specificity range 0.580 to 0.700 (range of 95% CI 0.530 to 0.740) | Very low certainty that MORES identifies men at high risk of osteoporosis; (rated down for serious risk of bias, serious indirectness, serious inconsistency, and very serious imprecision)
AUC | 4 studies; (6,285 participants) | AUC range: 0.728 to 0.870 (range of 95% CI 0.693 to 0.910) | Low certainty that MORES identifies men at high risk of osteoporosis; (rated down for serious risk of bias serious and serious imprecision)
HIP FRACTURE
FRAX
Sensitivity | 4 studies; (59,795 participants) | Sensitivity range 0.427 to 0.900 (range of 95% CI NR to 0.940) | Very low certainty that FRAX identifies men at high risk of hip fracture; (rated down for very serious inconsistency and serious imprecision)
Specificity | 4 studies; (59,795 participants) | Specificity range 0.360 to 0.906 (range of 95% CI 0.350 to NR) | Very low certainty that FRAX identifies men at high risk of hip fracture; (rated down for very serious inconsistency and serious imprecision)
AUC | 9 studies; (506,888 participants) | AUC range: 0.674 to 0.930 (range of 95% CI 0.625 to 0.950) | Low certainty that FRAX identifies men at high risk of hip fracture; (rated down for serious inconsistency and imprecision)
Garvan
Sensitivity | 3 studies; (484,846 participants) | Sensitivity range: 0.356 to 0.9 (range of 95% CI NR to 0.985 | Low certainty that Garvan identifies men at high risk of hip fracture; (rated down for serious inconsistency, and imprecision)
Specificity | 3 studies; (484,846 participants) | Specificity range: 0.35 to 0.908 (range of 95% CI 0.33 to NR) | Low certainty that Garvan identifies men at high risk of hip fracture; (rated down for serious inconsistency, and imprecision)
AUC | 3 studies; (484,846 participants) | AUC range: 0.71 to 0.773 (range of 95% CI 0.67 to 0.855) | Moderate certainty that Garvan identifies men at high risk of hip fracture; (rated down for serious imprecision)
QFracture
AUC | 5 studies; (2,573,876 participants) | AUC range: 0.609 to 0.875 (range of 95% CI 0.660 to 0.863) | Low certainty that QFracture identifies men at high risk of hip fracture; (rated down for serious risk of bias, inconsistency, and imprecision)
MAJOR OSTEOPOROTIC FRACTURE
FRAX
Sensitivity | 3 studies; (53,767 participants) | Sensitivity range 0.027 to 0.900 (range of 95% CI 0.0003 to 0.940) | Very low certainty that FRAX identifies men at high risk of MOF; (rated down for serious risk of bias, inconsistency and imprecision)
Specificity | 3 studies; (53,767 participants) | Specificity range 0.330 to 0.991 (range of 95% CI 0.340 to 0.996) | Very low certainty that FRAX identifies men at high risk of MOF; (rated down for serious risk of bias, inconsistency and imprecision)
AUC | 9 studies; (74,399 participants) | AUC range: 0.618 to 0.810 (range of 95% CI 0.620 to 0.850) | Very low certainty that FRAX identifies men at high risk of MOF; (rated down for serious risk of bias, inconsistency and imprecision)
QFracture
AUC | 5 studies; (2,573,739 participants) | AUC range: 0.640 to 0.739 (range of 95% CI 0.61 to 0.746) | Moderate certainty that QFracture identifies men at high risk of MOF; (rated down for serious imprecision)

### Key Question 2 Summary

KQ 2 Among [underlined: male Veterans] not identified by a history of low-trauma fracture, is there a tool or combination of risk factors that identifies patients at highest risk of osteoporosis or major osteoporotic fracture?

To address this question, we evaluated the subset of studies conducted specifically in male Veterans not identified via history of low-trauma fracture. The studies described here represent a subset of the studies included above for KQ 1. These studies examined individual risk factors or risk assessment tools and their association with osteoporosis or osteopenia, defined by T-scores on DXA, and fracture defined by diagnosis codes. Eight studies^26,28,48,51,53,54,56,67^ (n = 26,469) examined risk assessment tools among male Veterans, and of these, three^26,48,56^ (n = 24,848) were conducted in populations of special interest where fracture risk is considered higher than the general population. Eleven studies^51,69–78^ assessed individual risk factors for low BMD and/or fracture broadly categorized as medical conditions (ie, HIV infection, osteomyelitis, elevated BMI, chronic kidney disease, vitamin D deficiency, chronic pancreatitis), or exposures (eg, medication use), or combinations of conditions and exposures in specific Veteran populations. Overall, there was considerable conceptual heterogeneity across studies about how risk factors were used in tools, how independent risk factors were derived (ie, patient report vs electronic health record review), and how outcomes were defined (eg, diagnosis codes, T-scores). All included studies of risk factors were at high or unclear risk of bias.

Among male Veterans at average risk of osteoporosis and/or fracture, FRAX and OST were assessed most often. When comparing male Veterans to other male populations, FRAX and OST perform similarly. The OST/OSTA demonstrated poor-to-good discriminatory ability in predicting osteoporosis (AUC 0.632 to 0.740) among general populations and among Veterans (AUC 0.670 to 0.890). Among general populations, FRAX demonstrated poor-to-excellent discriminatory ability (AUC 0.596 to 0.870) across all included studies and good discriminatory ability (AUC 0.72; 95% CI 0.67 to 0.78) in 1 Veteran study when predicting osteoporosis. The Mscore and VA-FARA are “homegrown” VA tools examined in 1 study each^28,67^ While Mscore appears to better predict osteoporosis than VA-FARA, there are insufficient data to recommend one approach over another, or to recommend any of these tools other than FRAX and OST, which have been studied and validated across broader populations. In sum, among male Veterans at high risk for fracture, risk assessment tools had low-to-moderate discriminant validity.

Three studies^26,48,56^ (n = 24,848) were conducted on populations of special interest for the VA and who may be at heightened risk of osteoporosis and fracture: 1) human immunodeficiency virus (HIV) and hepatitis C virus (HCV) infection (FRAX)^26^; 2) history of androgen deprivation therapy (ADT) for localized prostate cancer (FRAX)^48^; and 3) rheumatoid arthritis (OST).^56^ Among male Veterans, FRAX appears to underestimate risk of fracture in HIV and HCV infection, as well as in those treated with ADT. Compared to its performance in average risk male Veteran populations, OST appears to perform suboptimally for predicting osteoporosis in male Veterans with rheumatoid arthritis. Among male Veterans, we identified limited evidence supporting individual risk factors for osteoporosis and/or fracture.

### Key Question 3 Summary

KQ 3 What system-level interventions improve uptake of osteoporosis screening among people without a history of low-trauma fracture?

In total, 20 studies were included examining system-level interventions to improve the uptake of osteoporosis screening among people without a history of low-trauma fracture. Because some studies had more than 1 active intervention arm, a total of 24 intervention arms are described across the 20 studies. Interventions for these studies fell into 8 different categories: 1) provider education (5 studies^92–96^), 2) provider and patient education (3 studies^93,97,98^), 3) provider-focused reminders (4 studies^99–102^), 4) clinical decision support tools (1 study^103^), 5) patient navigation (2 studies^97,104^), 6) patient risk assessment (3 studies^105–107^), 7) patient self-referral (4 studies^108–111^), and 8) patient-focused reminders (1 study^102^).

Overall, a majority of the identified systems-level interventions in the literature target providers (12 studies), and most of the literature excluded men or had limited males in the included samples. Overall, provider-focused approaches have mixed effectiveness in improving uptake of osteoporosis screening. Provider education-only interventions (eg, CME) show no improvements in uptake of osteoporosis screening (4 studies). Yet provider-focused reminder systems (4 studies) improve uptake of osteoporosis screening via BMD. Clinical decision support tools that combine tailored risk-based education for patients and tailored provider recommendations at the point of clinic visit show promise but have only been evaluated in 1 study. Combining provider interventions with targeted patient-focused approaches improves the impact of the combined intervention on uptake of osteoporosis screening.

Ten studies evaluated the effect of patient-focused approaches on uptake of osteoporosis screening. Overall, patient-focused approaches of patient navigation (2 studies), patient risk assessment (2 studies), patient reminders (1 study), and self-referral systems (4 studies) improve osteoporosis screening via BMD. System-redesign approaches that allow patients to self-refer for screening may be more effective when using fixed appointments than open invitations to self-refer without a fixed appointment. Coupling patient approaches with provider-focused approaches only marginally increased effectiveness when compared to usual care.

Risk of developing osteoporosis, hip fracture, or MOF were deemed the outcomes critical to decision-making. Thus, these are the outcomes for which we conducted certainty of evidence (COE) ratings. These COE judgments reflect the degree of confidence we have in our summary findings. For each outcome of interest, we present the COE first by outcome modeled (ie, osteoporosis, hip fracture, MOF) per each of the major risk assessment tools, and then by sensitivity, specificity, and AUC. COE ratings are summarized below, with supporting information provided in Table 15.

- We found very low COE to support that provider education alone impacts uptake of osteoporosis screening and low COE when provider education is bolstered with patient educational approaches.
- We found very low COE for provider-focused reminders and clinical decisions support tools on the uptake of osteoporosis screening.
- For patient-focused interventions, we found at least low COE for all identified interventions (patient navigation, patient risk assessment, patient reminders patient self-referral).

Table 15 Certainty of Evidence for Uptake of Osteoporosis Screening by Intervention Type

Intervention | Number of Studies (N) | Findings | Certainty of Evidence (Rationale)
Provider-focused Interventions
Provider education | 4 randomized (14,827 participants) | Summary OR 0.98; (95% CI 0.39 to 2.50) | Very low certainty of increased screening; (rated down for serious risk of bias, inconsistency, and imprecision)
Provider education | 1 nonrandomized (672 participants) | Intervention Pre: 6.9%; Intervention Post: 33.6%; Control Pre: 9.8%; Control Post: 34% | Very low certainty of increased screening; (rated down for serious risk of bias, inconsistency, and imprecision)
Provider and patient education | 3 randomized (15,547 participants) | OR range 0.97 to 2.39; (95% CI 0.80 to 6.04) | Low certainty of increased screening; (rated down for serious risk of bias and inconsistency)
Provider reminder | 2 randomized (4,044 participants) | OR range 1.29 to 5.47; (95% CI 0.94 to 15.57) | Very low certainty of increased screening; (rated down for serious risk of bias, inconsistency, and imprecision)
Provider reminder | 1 randomized (10,354 participants) | ß = −2.12; (SE 0.96) | Very low certainty of increased screening; (rated down for serious risk of bias, inconsistency, indirectness, and very serious imprecision)
Provider reminder | 1 nonrandomized (4,660 participants) | 2.31; (95% CI 1.55 to 3.43) | Very low certainty of increased screening; (rated down for serious risk of bias and inconsistency)
Clinical decision support tools | 1 Interrupted time series (18,309 participants) | Percent change: 3.4%; (95% CI 2.03 to 4.68) | Very low certainty of increased screening; (rated down for serious risk of bias and inconsistency)
Patient-focused Interventions
Patient navigation | 1 randomized (119 participants) | OR 8.00; (95% CI 3.11 to 20.6) | Low certainty of increased screening; (rated down for serious risk of bias and inconsistency)
Patient navigation | 1 Interrupted time series (564 participants) | Patient education + navigation vs usual care: p < .001 | Very low certainty of increased screening; (rated down for serious inconsistency and indirectness)
Patient risk assessment | 2 randomized (262+ 4,685 participants) | Risk ratio 2.2; (95% CI 1.2 to 4.1); Percent difference 6% (p = 0.001) | Low certainty of increased screening; (rated down for serious risk of bias and inconsistency)
Patient risk assessment | 1 randomized (34,229 participants) | Major osteoporotic fracture sub-hazard ratio : 0.986; Hip fracture sub-hazard ratio: 1.002 | Low certainty of decreased fracture; (rated down for serious risk of bias and inconsistency)
Patient Self-referral | 4 randomized (19,840 participants) | OR range 1.31 to 4.87; (95% CI 0.96 to 7.14) | Low certainty of increased screening; (rated down for serious risk of bias and imprecision)
Patient reminder | 1 randomized (10,354 participants) | Patient mailed reminder 21.4% (unadjusted); Usual Care: 10.8% (unadjusted) | Low certainty of increased screening; (rated down for serious risk of bias and inconsistency)

## PRIOR SYSTEMATIC REVIEWS

### Relevance to Key Question 1

Two prior systematic reviews have examined the use of screening in the prediction of osteoporosis^113^ or osteoporotic fractures,^114^ though only Shekelle et al^113^ specifically examined clinical (non-imaging) tools in men. Shekelle et al^113^ reported low quality evidence that the OST has at least comparable accuracy in predicting DXA-determined osteoporosis in men when compared to calcaneal ultrasound. These authors also reported that while calcaneal ultrasound does not appear to be particularly effective at predicting DXA-determined osteoporosis in men, it may be a strong independent predictor of osteoporotic fracture. Allon et al^114^ specifically examined the use of imaging tools like quantitative computed tomography (QCT), magnetic resonance imaging (MRI), and ultrasound as an alternative for DXA in predicting fragility fractures.^114^ They recommended initial screening for risk of fracture with a risk questionnaire, with those patients identified as higher risk being referred for ultrasound, and then, if low bone density is observed, for DXA.^114^

Prior reviews only identified 1 non-invasive clinical risk prediction tool among men. We built on prior reviews by synthesizing the evidence on the utility of 18 different non-imaging clinical risk prediction tools as first-line screening for osteoporosis. Next, prior reviews found limited information on patient-important outcomes of fractures. We synthesized evidence on the utility of screening tools for risk of hip fractures (15 studies), MOF (16 studies), and osteoporosis via BMD (24 studies). Like prior reviews, we found mostly low certainty of evidence across all outcomes, regardless of the clinical risk prediction tool.

### Relevance to Key Question 2

Shekelle et al^113^ is the only prior systematic review that has specifically examined risk factors for osteoporosis and osteoporotic fractures in men.^113^ With respect to increased risk for osteoporosis in men, Shekelle’s team found high quality evidence for an association with age, low body weight, physical inactivity, and weight loss, and moderate quality evidence for an association with spinal cord injury and with prolonged systemic corticosteroid therapy and androgen deprivation in the context of prostate cancer treatment. Low quality evidence was found suggesting that there was no association with diabetes mellitus type II and risk for osteoporosis in men. With respect to osteoporotic fractures, their review found moderate quality evidence for an association of alcohol use, and low-quality evidence for an association with spinal cord injury. One recent review narratively synthesized studies that had used artificial intelligence (AI) to identify groups at risk for osteoporosis or fractures.^115^ These authors concluded that a large range of risk factors have been noted and called for a grouping of risk factors to aid in a more comprehensive approach to risk identification. Building upon the findings of Shekelle et al^113^ and in line with Cruz et al^115^ the current review identified risk factors for osteoporosis and osteoporotic fractures in men that can be grouped into 3 general categories: risk associated with behavior (eg, smoking, physical activity); risk associated with existing health conditions (eg, posttraumatic stress disorder, HIV); and risk associated with medications (eg, prednisone). We also identified risk factors and grouped similarly into factors associated with medical conditions (eg, HIV infection, elevated BMI, chronic kidney disease, chronic pancreatitis) or exposures (eg, medication use). In contrast to prior reviews, ours is the first systematic review key question to specifically focus on risk factors for osteoporosis among male Veterans.

### Relevance to Key Question 3

Within the past decade several systematic reviews have evaluated the effect of physician- and patient-directed interventions on initiation of BMD scanning in patients at risk for osteoporosis. Little and Eccles^116^ reviewed RCTs evaluating a wide range of interventions to increase BMD scanning or to initiate medication in individuals post-fracture who were at high risk for osteoporosis, including patient education or reminders, physician alerting, a combination of patient education and physician alerting, or physician and patient education. Results suggested positive effects of the interventions in increasing BMD scanning, with small to medium heterogeneity among the included studies. Laliberté et al^117^ conducted a systematic review and meta-analysis of a range of interventions targeting PCPs and patients at risk for osteoporosis, most of which were multifaceted and included patient education, physician notification, and/or physician education. Results suggested that the interventions increased the incidence of BMD testing for both at-risk and high risk patients, with the effects more pronounced for high risk patients. These authors concluded that involvement of a wider range of health professionals beyond PCPs in interventions targeting osteoporosis screening and treatment may address both patient- and physician-related barriers to care. A recent Cochrane systematic review included an analysis of interventions to increase guideline-consistent behavior for the management of osteoporosis including BMD testing and prescription of osteoporosis medication. Results found high quality evidence for a GP alerting system combined with patient-directed intervention (patient education and reminder to see their GP) on improving these outcomes, and further evidence that GP alerting alone is probably effective such that adding the patient-directed component may not afford additional benefit.^118^ Finally, Morfeld et al^119^ included initiation of BMD testing or medication in their review of RCTs of patient education for osteoporosis prevention and found 2 studies that suggested that patient education improved these outcomes over usual care. Taken together, prior reviews have found that a range of patient- and physician-directed interventions may be effective at increasing BMD testing in individuals at risk for osteoporosis. Our review aligns with the findings of these studies and provides some nuances to the impacts of these types of interventions on uptake of osteoporosis screening via BMD. Overall, we found no evidence of impact of provider education as a standalone strategy. More robust provider-focused interventions that are integrated into clinical workflow such as clinician reminder systems and clinical decision support tools significantly increased the uptake of BMD screening. Combining provider interventions with targeted patient-focused approaches improves the impact of the combined intervention on uptake of osteoporosis screening over provider-only approaches. Patient-focused approaches of patient navigation, patient risk assessment and feedback, patient reminders, and self-referral systems improve osteoporosis screening via BMD.

## CLINICAL POLICY IMPLICATIONS

Current guidelines suggest screening for osteoporosis in men above the age of 70, and in those aged 50-69 years if additional risk factors are present, such as hypogonadism, smoking, and steroid use, among others.^5^ In practice, clinical risk prediction tools can help identify patients at heightened risk of osteoporosis and/or fracture. However, these tools (eg, FRAX) have been developed primarily using female populations. Notably, in women above the age of 70 in the UK, systematic community-based screening using FRAX has been found to reduce the risk of hip fracture, but not major osteoporotic fracture. The benefit of systematic screening in men is unclear. Thus, the provider must weigh the risks and benefits of routine screening, including increased demand on DXA utilization and interpretation, low dose radiation with DXA, increased identification of low bone density and osteoporosis, increased use of osteoporosis medication and potential adverse events, and potential reduction in fracture risk.^112^

In the current review, we identified few high quality (low ROB) studies examining the utility of clinical risk prediction tools and individual risk factors for predicting osteoporosis and low-trauma fracture in men. Of risk prediction tools, FRAX had the greatest number of studies among male populations. Consistent with the literature in post-menopausal women, FRAX appeared to better predict hip fracture versus MOF in men, with comparable predictive abilities to those reported in women.^120^ A similar pattern was also observed with Q-fracture, which tends to perform similarly to FRAX in practice.^24^ Overall, these data suggest good clinical utility of FRAX and Q-fracture in predicting fractures among men. However, it is important to note that studies examining risk prediction tools were heterogeneous in population (ie, fracture prevalence), follow-up length, and in how risk tools were implemented (ie, which risk factors were included). Interpretation of findings was further limited by missing data on sensitivity and specificity of risk prediction tools. As such, no definitive conclusions can be made regarding whether one fracture risk prediction tool performs better than another in men, and further investigation is warranted. A large gap in the literature likewise exists for the use of risk tools to predict male osteoporosis. MORES and OST appeared to predict osteoporosis reasonably well; however, most studies were at high risk of bias, and thus additional high quality studies are needed to determine the value of these tools in male populations.

It is worth noting that the purpose of OST is to screen for osteoporosis, not to assess risk of fracture, nor to trigger pharmacological interventions aimed at reducing fracture risk. As such, its good sensitivity across most studies (regardless of specificity), combined with its simplicity, renders it a useful screening tool for identifying male Veterans who may benefit from BMD testing for further risk stratification.^29^ Yet across studies there is a lack of discernment between osteoporosis of the hip versus other sites when defining osteoporosis. This is important for men as low BMD of the hip better predicts fracture in men than low BMD of the spine, as men tend to develop more degenerative changes of the spine (eg, osteophytes) and vascular calcifications that may falsely raise BMD at this site. Therefore, focusing on tools that may predict hip osteoporosis as an outcome, as opposed to low BMD at other sites, may better identify men at higher of fracture.

Lastly, it is important to note that there is a wide range of ease of implementation of the 18 unique clinical risk prediction tools we identified in this review. Some have few, easily obtained variables like the OST which only includes age and weight. Others such as the QFracture have over a dozen variables that may require a mix of patient-reported and EHR-derived components to compute risk scores. When implementing a screening tool into clinical practice careful consideration needs to be paid to how the data to populate the clinical risk tool will be gathered (eg, patient-reported, health records) and integrated into clinical workflow to minimize provider and patient assessment burden. With the expanding use of natural language process (NLP) methods in medicine, such EHR-based approaches to populating risk prediction tools may become more feasible and allow for use of available EHR data to identify high-risk cases that would have otherwise gone undetected.

## LIMITATIONS

Our review has several strengths, including a protocol-driven design, a comprehensive search of nearly 9000 unique abstracts and 600 full-text reviews, inclusion of EPOC designs best suited to assess organizational-level interventions (KQ 3), and careful quality assessment. Both our review and the literature, however, have limitations. While we identified 67 unique studies, the total of identified studies when synthesized by tool and intervention for many outcomes was small, and most of literature we identified had design limitations that affected study quality. Further, 9 of our synthesis suffered from high heterogeneity that was not easily explained via single sources and, for KQ 1, is likely attributable to differences in populating variables for risk assessment tools (eg, EHR-derived vs patient reported), thresholds, choice of reference databases, and prevalence in populations used to assess tools. For KQ 3, heterogeneity was attributable to a combination of intervention composition, populations assessed (eg, women only vs men with ADT), and timing of outcome assessments.

Importantly, a major limitation of the literature is limited evidence on the direct (ie, head-to-head) comparison of clinical risk prediction tools (KQ 1). Thus, we are overall less confident in the observed differences and similarities between tools assessed across different populations of men. Moreover, the majority of the studies and samples for KQ 3 were comprised of women. While we may presume system-level interventions to promote uptake of osteoporosis screening via BMD may perform similarity among men and women, there may be sex-specific differences in receptivity to these screening promotion approaches. Other limitations are detailed below.

### Publication Bias

Given the small number of studies, statistical methods to detect publication bias are not useful. Other strategies, such as searching ClinicalTrials.gov for completed but unpublished studies, are not a particularly effective way to identify publication bias.^121^ Hence, we did not conduct formal publication bias analysis.

### Study Quality

We were also limited by the existing literature. Most of the identified literature was assessed as unclear or high ROB. For study quality in KQ 1 and KQ 2 of clinical risk prediction studies we used the QUADAS-2. In these studies, use of random sampling or consecutive patients for patient selection bias and potential bias introduced by knowledge of the reference standard on index test interpretation contributed to judgments of higher risk. For the 11 cohort studies that assess individual risk factors using an adapted Newcastle-Ottawa ROB approach, inadequate follow-up of cohorts was the most common ROB domain judged to be problematic, along with issues of outcome assessment (KQ 2). In KQ 3, adequacy of randomization, comparability of groups at baseline, and blinding were the greatest contributors to rating of unclear or high ROB.

### Applicability of Findings to the VA Population

Of the included studies in KQ 1 and KQ 2, 79% were conducted in studies exclusively comprised of men. For KQ 2, we focused exclusively on male Veterans. Males comprise the vast majority of VA users. Thus, the results of KQ 1 and KQ 2 are very applicable to the VA population. Yet, for KQ 3, most of the studies were among women only or among study samples dominated by women, and none were conducted in the VA health care system. While it is conceivable that systems-level interventions to promote screening behaviors may influence men and women equally, this is not known for certain. However, the findings presented here for the impact of systems-level interventions likely have applicability to any large health care system seeking to implement approaches to increase uptake of osteoporosis screening.

## RESEARCH GAPS/FUTURE RESEARCH

We identified several gaps in the existing literature that warrant further consideration. To systematically identify the existence of, and reason for, these gaps, we used an existing framework. Robinson et al^122^ propose the identification of gaps categorically using the PICOTS framework (population, intervention, comparator, outcome, timing, and setting) and classification by reason (insufficient or imprecise information, biased information, inconsistency and/or not the right information). Below we apply this framework to identify the gaps in the literature for KQ 1 and KQ 2 (Table 16) and KQ 3 (Table 17).

Table 16 Evidence Gaps and Future Research for Studies of Clinical Risk Prediction Tool and Risk Factors Among Male Veterans

Evidence Gap | Reason | Types of Studies to Consider
Population
- Studies with more racial and ethnic diversity similar to the VA population; - Special populations at elevated risk of fracture such as patients with HIV, ADT, thyroid cancer, PTSD, chronic pancreatitis, and medication use (eg, antipsychotic use, opiates, gabapentinoids) | - Insufficient information; - Not the right information | - Prospective cohort studies; - Retrospective cohort studies; - Cross sectional studies
Interventions
- VA-specific tools like the VA-FARA and Mscore; - Garvan risk assessment tool | - Insufficient information | - Prospective cohort studies; - Retrospective cohort studies; - Cross sectional studies
Comparators
- Limited studies assessing clinical risk tool in the same population of men; - Limited studies assessing validity to tools derived from EHR vs patient-reported outcomes in men; - Limited studies using race-/ethnicity-specific reference data for BMD in men | - Insufficient information | - Prospective cohort studies; - Retrospective cohort studies; - Cross sectional studies
Outcomes
- Studies focusing on hip osteoporosis in men; - Sensitivity and specificity of clinical risk assessment tools for hip fracture and MOF in men | - Insufficient information | - Prospective cohort studies; - Retrospective cohort studies; - Cross sectional studies
Setting
- Large, comprehensive health care systems | - Insufficient information | - Prospective cohort studies; - Retrospective cohort studies

Table 17 Evidence Gaps and Future Research for Studies of Systems-level Approaches to Improve Uptake of Osteoporosis Screening

Evidence Gap | Reason | Types of Studies to Consider
Population
- Limited studies conducted with average risk male-only populations; - Limited studies conducted with male populations at elevated risk (eg, ADT) | - Insufficient information; - Not the right information | - Cluster-randomized trials; - Controlled before and after; - Nonrandomized trials; - Interrupted time series
Interventions
- Patient-focused reminders; - Provider-focused reminders; - Clinical decision support systems; - Patient navigation | - Insufficient information | - Cluster-randomized trials; - Controlled before and after; - Nonrandomized trials; - Interrupted time series
Comparators
- Comparisons of different self-referral systems (eg, fixed appointment vs open invitation to self-schedule); - Provider reminders vs patient reminders; - Comparisons of different provider reminder systems (eg, actionable link vs static EHR-based reminders); - Factorial designs to evaluate incremental benefit of provider-focused approaches added to patient-focused approaches | - Insufficient information | - Cluster-randomized trials; - Controlled before and after; - Nonrandomized trials; - Interrupted time series; - Factorial trials
Outcomes
- Implementation feasibility of embedding clinical risk assessment tools into clinic workflow; - Intervention cost; - Cost effectiveness; - Osteoporotic fracture; - Provider burden | - Insufficient information | - Cluster-randomized trials; - Controlled before and after; - Nonrandomized trials; - Interrupted time series; - Step-wedge designs
Setting
- Large, comprehensive health care systems | - Insufficient information | - Cluster-randomized trials; - Controlled before and after; - Nonrandomized trials; - Interrupted time series

## CONCLUSIONS

The lifetime risk of an osteoporotic fracture in men over the age of 50 is between 20% and 30%.^1^ Although this is less than the overall prevalence in women, men have higher rates of fracture-related mortality than women. Screening to identify those at highest risk of fracture-related morbidity is standard practice for women but there is uncertainty about universal screening for men. Overall, we found little evidence that directly compared risk assessment tools within the same population of men. Among the risk assessment tools assessed, the OST has good discriminatory ability in predicting osteoporosis by DXA and had 2 easily obtainable variables. Tools such as FRAX, QFracture, and Garvan display poor to excellent discrimination in predicting hip fracture and MOF. Yet the COE for these outcomes was low or very low except for one outcome of interest (ie, Garvan hip fracture AUC rated moderate COE). For systems-level approaches to increase osteoporosis screening, we found that provider-focused strategies have mixed effectiveness in improving uptake of osteoporosis screening. Combining provider interventions with targeted patient-focused approaches improves the impact of the combined intervention on uptake of osteoporosis screening. Yet evidence for individual system approaches to increase osteoporosis screening is limited. When implementing a system of risk assessment and screening in a large health care system like the VA, careful consideration needs to be paid to impacts on provider workflow and patient assessment burden.