# RESULTS

## LITERATURE FLOW

For KQ 1 and KQ 2, we identified 5,863 studies through searches of MEDLINE^®^ (via PubMed^®^), Embase (via Elsevier), and CINAHL (via EBSCO) (Figure 1). An additional 406 articles were identified after conducting a MEDLINE^®^ update and reviewing bibliographies of relevant review articles for a total of 6,269 articles. After removing duplicates, there were a total of 5,011 articles. After applying inclusion and exclusion criteria to titles and abstracts, 364 articles remained for full-text review. Of these, 48 studies were retained for data abstraction. Of the 48 studies included, 39 were identified as unique studies. Of the 48 studies, 36 were cohort studies, 11 were cross-sectional studies, and 1 was a case-control study. Included studies were conducted in the United States (29), United Kingdom (4), South Korea (4), Canada (2), Portugal (2), Australia (2), Denmark (1), Israel (1), Japan (1), Norway (1), and Italy (1). There were 19 VA studies.

Figure 1 Literature Flow Chart: KQ 1 and KQ 2

^a^ Search results from Medline (1664), Embase (2219), CINAHL (831), manually identified (23), and Medline update (274) were combined.

^b^ 10 studies use overlapping same source populations.

^c^ 8 studies are included in KQ 1 and KQ 2.

For KQ 3, we identified 5,854 studies through searches of MEDLINE^®^ (via PubMed^®^), Embase (via Elsevier), and CINAHL (via EBSCO) (Figure 2). An additional 409 articles were identified after conducting a MEDLINE update and reviewing bibliographies of relevant review articles, for a total of 6,263 articles. After removing duplicates, there were a total of 4,276 articles. After applying inclusion and exclusion criteria to titles and abstracts, 235 articles remained for full-text review. Of these, 21 studies were retained for data abstraction. Of the 21 studies included, 20 were identified as unique studies. Of the 20 studies, 8 were individually randomized controlled trials (RCTs), 6 were cluster-randomized trials (CRTs), 1 was a controlled before-after study, 2 were time-series studies, and 3 were nonrandomized studies. Included studies were conducted in the United States (15), Canada (3), Denmark (1), and the United Kingdom (1). None of the studies were conducted in the VA.

Figure 2 Literature Flow Chart: KQ 3

^a^ Search results from Medline (2,331), Embase (1,349), CINAHL (297), manually identified (31), Medline update (268) were combined.

## EVIDENCE PROFILE

Table 2 shows the evidence profile of studies included in this systematic review. Appendices B and C contain detailed study characteristics for included studies.

Table 2 Evidence Profile of Included Studies

| KQ 1 and KQ 2 (n=48) | KQ 3 (n=20)
Study design | 36 Cohort; 11 Cross-sectional; 1 Case-control | 8 Randomized; 6 Cluster-randomized; 3 Nonrandomized; 1 Controlled before-after; 2 Interrupted time series
Number of participants | 12,225,464 | 114,538
Region | 29 US; 9 Europe; 4 South Korea; 2 Canada; 4 Other | 15 USA; 3 Canada; 1 Denmark; 1 UK
Population | 37 Men only; 11 Men and women | 1 Men only; 8 Men and women; 11 Women only
Median age (range) | 63.5 (45 to 80.4); 1 study NR; 2 studies reported age in several categories | 71.1 (51.5 to 82.0); 3 studies NR; 1 study reported age in several categories
Median % Male or Women (range) | 100% Men (7% to 100%); 0 studies NR | 99% Women (57% to 100%); 0 studies NR
Median % Race (range) | 89% White (37% to 100%); NR by 22 studies; 11% Black (1% to 100%); NR by 29 studies | 70% White (46% to 97%); NR by 18 studies; 14 % Black (12% to 37%); NR by 18 studies
Tool | 19 FRAX; 9 OST; 5 QFracture; 4 MORES; 4 Garvan; 6 Other | NA
Intervention type | NA | 5 Provider education; 3 Provider and patient education; 2 Patient navigation; 3 Patient risk assessment; 4 Self-referral; 4 Provider system reminder; 1 Patient system reminder; 1 Clinical support tool
Outcomes reported^a^ | 25 Osteoporosis or osteopenia via BMD; 16 Hip fracture; 17 Major Osteoporotic fracture; 11 All fracture | 19 Screening; 1 Fracture
Risk of bias | [underlined: QUADAS-2] ^b^; 18 At risk; 19 Low risk; [underlined: Newcastle-Ottawa]^c^:; 5 High risk; 5 Unclear risk; 0 Low risk; [underlined: Case-control Newcastle-Ottawa^c^:]; 1 Unclear | [underlined: Objective]^d^:; 2 Low risk; 12 Unclear risk; 2 High risk; 2 NA; [underlined: Patient-reported]^e^:; 3 Low risk; 1 Unclear risk; 1 High risk; 13 NA; [underlined: Interrupted time series]:; 1 Unclear risk; 1 Low risk

Abbreviations. NA=not applicable; NR=not reported

a Studies report more than 1 outcome type.

b Diagnostic test accuracy studies (29 in KQ 1 only and 8 in KQ 1 and KQ 2).

c Adapted Newcastle-Ottawa for cohort and case-control studies.

d Objective outcomes (ie, non–patient-reported outcomes) are not subject to a large degree of individual interpretation.

e Patient-reported outcomes are directly reported by the patient without interpretation of the patient’s response.

## ORGANIZATION OF RESULTS

### KQ 1—Tools

This section focuses on the general population of men encompassing civilian and Veteran populations. Given the variety of screening tools identified, first we focus on the established tools described by more than 3 studies. Within each tool section, we describe the outcomes reported by each respective tool (eg, fracture, osteoporosis). We also describe any adaptions or slight modifications of the established tool that have been evaluated in the literature (eg, FRAX-A). Subsequently, we describe tools that were evaluated in patient populations at elevated risk for osteoporosis. Last, we describe the tools reported by only 1 or 2 studies.

### KQ 2—Tools and Risk Factors in Male Veterans

This section focuses on male Veteran populations only, including established risk assessment tools and studies identifying additional risk factors potentially salient to the Veteran population. With guidance from our operational partners, we focused on the tools and risk factors that identify Veterans at highest risk of osteoporosis or fracture. Some of these tools overlap with tools described in KQ 1, but with a specific focus on male Veterans. Thus, some studies included in KQ 1 results are also mentioned in KQ 2 and identified accordingly. Within this section, we identify the tools among general male Veteran populations as well as Veterans at elevated risk (eg, HIV-positive, on androgen deprivation therapy). The independent risk factors are grouped into medical conditions only and medical conditions and exposures.

### KQ 3—Interventions

This section focuses first on systems-level interventions designed to impact providers and then on systems level interventions aimed at patients. Within each patient or provider section, studies are ordered from least intensive to most intensive intervention strategies.

## KEY QUESTION 1 Among males not identified by a history of low-trauma fracture, is there a clinical risk tool (eg, FRAX) that identifies patients at highest risk of osteoporosis or major osteoporotic fracture?

### Characteristics of Included Studies

We identified 37 studies that met our inclusion criteria. Included studies evaluated 18 different clinical risk tools (eg, FRAX, FRAX-A, FRAX-A+, OST/OSTA, QFracture, MORES, Garvan, VA-FARA, FRA HS model 1 and model 2, Korean Fracture Risk Score, Korean risk assessment, FRC, Mscore, Model I, II, and IV, Weight-based calculation). Appendix G presents a complete list of the tools and their respective components. Nine studies reported on more than 1 tool within the same population. There were 19 studies that assessed the FRAX risk assessment tool or a modified version of the FRAX risk assessment tool. Nine studies assessed the OST/OSTA. QFracture (2 different versions) was used in 5 studies. Four studies evaluated the MORES risk tool. The Garvan tool was assessed in 4 studies. The remaining tools were each evaluated in 1 study. The FRAX tool was assessed with all 3 outcomes: major osteoporotic fracture (MOF), hip fracture, and osteoporosis. The OST and the MORES, however, were only evaluated with osteoporosis as an endpoint in the identified studies. The QFracture and the Garvan tools were only compared to major osteoporotic fracture and hip fracture.

### KeyKey Points

- We found 37 studies evaluating 18 different risk assessment tools.
- Limited evidence was identified that directly compared tools within the same population.
- Among men not identified via prior diagnosis of osteoporosis, the OST/OSTA has good discriminatory ability in predicting osteoporosis by DXA with 2, easily obtainable variables (AUC ranging from 0.632 to 0.890).
- Tools predicting osteoporosis (FRAX, MORES) reported AUC ranges from 0.596 to 0.870. High levels of heterogeneity were present.
- Tools predicting hip fracture and MOF (FRAX, QFracture, Garvan) all reported AUCs ranging from 0.609 to 0.930 for hip fracture and 0.618 to 0.810 for MOF. High levels of heterogeneity were present.
- Among men not identified via prior fracture, the FRAX risk assessment tool has better discrimination in predicting hip fracture than major osteoporotic fracture and osteoporosis diagnosis.
- Qualitatively, study location, patient age, or race did not correlate with low/moderate versus excellent discrimination.
- Limited evidence was identified for use of FRAX in special populations such as individuals with HIV and those on androgen deprivation therapy (ADT), but was generally found to perform worse among these groups.
- Limited evidence was identified using modified versions of the FRAX risk assessment tool.
- Limited evidence was identified for all other tools.

### C:\Users\ew78\AppData\Local\Microsoft\Windows\INetCache\Content.Word\Findings.pngDetailed Findings

For KQ 1, we present the detailed results ordered by clinical risk tool and, within each tool, by outcome. Details of study characteristics are in Appendix B.

### FRAX Risk Assessment Tool

The FRAX risk assessment tool (https://www.sheffield.ac.uk/FRAX/) was developed and independently validated by large international cohort studies including data from hundreds of thousands of patients. This tool incorporates multiple clinical risk factors independent of BMD (such as age, sex, weight, height, ethnicity, race, parental hip fracture, prior fracture, tobacco and alcohol use, glucocorticoid use, and rheumatoid arthritis) and secondary osteoporosis. There is the option of including femoral neck BMD to calculate a 10-year probability of hip or major osteoporotic fracture. Unlike other calculators, it does not include a history of falls.^24^ Per Bone Health Osteoporosis Foundation guidelines, in the US and some other countries, the FRAX risk assessment tool is used in patients with osteopenia to determine the need for osteoporosis treatment based on treatment thresholds above 20% for major osteoporotic fracture or 3% for hip fracture.

Nineteen studies—all of which used cohort or cross-sectional designs—evaluated the FRAX risk assessment tool without BMD or a modified version of the tool in predicting 1 or more clinical outcome: major osteoporotic fracture, hip fracture, or osteoporosis (by DXA) among men. The comparator varied by study and included other fracture prediction tools, fracture rate, and/or BMD. Seven studies were conducted in the United States,^25–31^ 5 in Europe (Denmark, Norway, Portugal, and 2 in the UK),^32–36^ 4 in Asia (Israel, Japan, and 2 in South Korea),^37–40^ 2 in Canada,^41,42^ and 1 in Australia.^43^ Twelve studies were among all male^25–32,34–37^ populations and 2 studies were conducted specifically among male Veterans.^26,28^ Three studies, which were all conducted in the United States, were among men age > 65–70 years only.^25,29,30^

#### Major Osteoporotic Fracture (MOF)

Nine studies^25,30,33,36,39–43^ evaluated the FRAX risk assessment tool in predicting MOF. Four studies had low risk of bias^25,30,42,43^ and 5 were considered at risk^33,36,39–41^ of bias. Individual study sample sizes range from 683 to 1,054,815 patients. Prevalence of major osteoporotic fracture ranged from 1.7% to 9.9% of the study populations.

Individually, most of the studies found the FRAX risk assessment tool to have poor to fair discrimination in predicting MOF (AUCs ranging from 0.618 to 0.810) (Figure 3). (Note, in general, an AUC of 0.5 is considered to mean no discrimination, 0.7 to 0.8 is acceptable discrimination, 0.8 to 0.9 is excellent discrimination, and > 0.9 is outstanding discrimination.^44^) Six studies^30,33,36,39–41^ were deemed to have sufficient conceptual homogeneity to be included in a quantitative synthesis. The 2 remaining studies^25,42^ assessed populations that overlapped with 2 of the more recent studies^30,41^ included in the quantitative synthesis and so were excluded. Five of the 6 studies included in the quantitative synthesis were evaluated as at risk in terms of ROB (Figures 10 and 11). Significant statistical heterogeneity was present (I^2^ 92.5%; Q 53.4). The 2 studies not included in the forest plot had similar reported AUCs of 0.63^25^ (no 95% CI reported) and 0.61^42^ (95% CI 0.56 to 0.65).

Figure 3 FRAX Tool Compared to Major Osteoporotic Fracture

#### Hip Fracture

Nine studies^25,30,32,35,36,40–43^ evaluated the FRAX risk assessment tool in predicting hip fracture rates. Six studies had low risk of bias (ROB)^25,30,32,35,42,43^ and 3 were at risk.^36,40,41^ Individual study sample sizes range from 683 to 424,336 patients. Prevalence of hip fracture ranged from 0.4% to 8.9% (unable to calculate in 2 studies^40,41^).

Individually, most studies found the FRAX risk assessment tool to have better discrimination in predicting hip fracture (AUC ranging from 0.67 to 0.93) than major osteoporotic fracture (Figure 4) Of the 5 studies^30,36,40,41,43^ that assessed both outcomes, discrimination was consistently better for hip fracture compared to major osteoporotic fracture.

Figure 4 FRAX Tool Compared to Hip Fracture

#### Osteoporosis

Four studies^27,29,31,37^ evaluated the FRAX risk assessment tool in predicting diagnosis of osteoporosis by DXA. One study^31^ had low ROB and 3 were at risk^27,29,37^of bias. Individual study sample sizes range from 520 to 4043 patients. The prevalence of osteoporosis across studies ranged from 5.3% to 25.3%. The prevalence of osteoporosis in 1 study population was not reported.^37^

Individually, most studies found the FRAX risk assessment tool to have poor discrimination in predicting osteoporosis by DXA (AUCs ranging from 0.596 to 0.790). Three of the studies^27,29,31^ could be included in quantitative synthesis (Figure 5). One study^31^ had higher prevalence of 25.3% compared to the other 2 included studies^27,29^ (4.5% and 5.3%). Significant statistical heterogeneity was present (I^2^ 94.5; Q 36.3). There was variation across studies in what reference populations were used to calculate T-scores (eg, NHANES III female, NHANES III male, Young adult mean)

The 1 study^37^ not included in the forest plot reported results for men < 75 years of age and men ≥ 75 years separately. AUCs for these groups were 0.63 (95% CI 0.49 to 0.77) for men < 75 years and 0.67 (95% CI 0.59 to 0.75) for men ≥ 75 years.

Figure 5 FRAX Tool Compared to Osteoporosis

#### FRAX Risk Assessment Tool with Modifications

Due to limitations identified in predicting fracture risk in certain individuals, modifications to the FRAX risk assessment tool have been proposed. These include modification when the spine BMD is disproportionately lower than the hip BMD, in individuals with diabetes,^45^ and in individuals on high doses of glucocorticoids,^46^ among others.^47^ Four studies^26,28,34,41^ included in this review evaluated a modified FRAX risk assessment tool. The 2 studies^26,34^ in men with HIV discussed above also calculated FRAX risk assessment scores using HIV as a secondary cause of osteoporosis. In the study conducted at the VA,^26^ the modified FRAX scores changed the observed/expected ratio for MOF for men with HIV 1.62 to 1.20 (95% CI 1.08 to 1.34) and from 4.52 to 2.66 (95% CI 2.17 to 3.26) for hip fracture. For MOF, none of the men met the > 20% threshold endorsed by the NOF, so the age-specific thresholds (6.3% to 13.4% in 50–70-year-olds) endorsed by the European osteoporosis societies were utilized. For hip fracture, the > 3% hip fracture threshold endorsed by the NOF was utilized. Among men with HIV using these thresholds, the sensitivity for MOF was 6.4% and hip fracture was 3.2%. The sensitivity among men without HIV was 2.6% for MOF and 0% for hip fracture. In the second study conducted in the UK,^34^ utilizing HIV as a secondary cause of osteoporosis changed the sensitivity of the modified FRAX risk assessment tool from 23% to 31% and specificity from 88% to 75%. One study that investigated a modified FRAX score, coined “e-FRAX,” that involved risk factor ascertainment via EHR.^28^ In the e-FRAX tool, parental hip fracture was the only risk factor assumed to be absent since documentation of this is known to be poor in the EHR. FRAX had better accuracy than e-FRAX (AUC 0.72 [95% CI 0.67 to 0.78] vs 0.65 [95% CI 0.59 to 0.71]) for predicting osteoporosis in this study. The fourth study^41^ was conducted in Canada and included 5615 men (9.2% total included). This study was at risk for bias. Four modified FRAX risk assessment models were developed based on different combinations of clinical risk factors included in FRAX and administrative data. AUCs for these modified FRAX scores for MOF were 0.584 (95% CI 0.553 to 0.615) for FRAX (age-sex), 0.624 (95% CI 0.594 to 0.654) for FRAX (age-sex-fracture), 0.616 (95% CI 0.586 to 0.646) for FRAX A (ie, FRAX, except for BMD, BMI, and parental hip fracture), and 0.648 (95% CI 0.619 to 0.677) for FRAX A+ (ie, FRAX A, plus a comorbidity score, number of hospitalizations in the 3 years prior, depression, and dementia). AUCs for the modified FRAX risk assessment scores for hip fracture were 0.663 (95% CI 0.612 to 0.714) for FRAX (age-sex), 0.657 (95% CI 0.605 to 0.709) for FRAX (age-sex-fracture), 0.648 (95% CI 0.598 to 0.698) for FRAX A, and 0.676 (95% CI 0.626 to 0.727) for FRAX A+.

#### FRAX Risk Assessment Tool in Patients at Higher Risk

Three studies^26,34,48^ evaluated the FRAX risk assessment tool in special populations; in men with HIV in 2 of the studies^26,34^ and in men undergoing androgen deprivation therapy (ADT) in 1.^48^ One of the studies^26^ focusing on men with HIV was conducted at the VA and included 24,451 Veterans. The observed/expected ratio of MOF for men with HIV was 1.62 (95% CI 1.45 to 1.81) versus for men without HIV 1.29 (95% CI 1.19 to 1.40) with a p-value of 0.03 for the difference between men with and without HIV. For hip fracture, the observed/expected ratio was 4.52 (95% CI 3.68 to 5.53) for men with HIV versus men without HIV 3.56 (95% CI 3.03 to 4.18). This study was at risk of bias. The second study^34^ of men with HIV was conducted in the UK with younger men aged 38 to 51 years. This study was low risk of bias and included 168 men. It utilized a threshold of ≥ 7.5% for the FRAX risk assessment tool in predicting osteoporosis (T-score ≤ −2.5) or low bone density for age (Z-score ≤ −2.0) by DXA. With this threshold, the sensitivity was 23% and specificity was 88%. The third special population study^48^ evaluated FRAX prediction of MOF or hip fracture in men undergoing androgen deprivation therapy. This low ROB study included 115 Veterans with a mean age of 77 years. Based on the NOF thresholds of risk of major osteoporotic fracture ≥ 20% or risk of hip fracture ≥ 3%, FRAX without BMD recommended treatment in 54% of Veterans. If treatment was based on T-score by DXA alone, 35% would be recommended for treatment due to T-score ≤ −2.5, 54% for T-score ≤ −2.0, and 69% for T-score ≤ −1.5. Note, no AUCs were reported in the studies of special populations.

### Osteoporosis Self-assessment Tool (OST) and Osteoporosis Self-assessment Tool for Asians (OSTA)

#### Osteoporosis

The OSTA was first established to predict osteoporosis among Asian women and is calculated using the following formula: OSTA = (weight in kg – age in years) × 0.2. The result is rounded down to the nearest whole number and categorized as low risk (> −1), moderate risk (−1 to −4), or high risk (< −4). Subsequently, the OST was validated in non-Asians using the same calculation and different cutoff values. A cutoff of OST < 2 was predictive of osteoporosis by DXA in Caucasian women.^49^

Seven studies evaluated the OST, including 5 prospective cohort studies^29,50–53^ and 2 cross-sectional studies.^28,54^ One cross-sectional study^55^ utilized the OSTA. Using the QUADAS, 1 of the OST studies^28^ and the 1 OSTA study^55^ were determined to have a low risk of bias; the remaining studies were considered at risk of bias.

The eight included studies comprised 6,075 participants in total. The mean/median age of participants ranged from 63.5 to 80.4 years. Six of the studies were mostly white (68.5% to 100%), while 1 study utilized data only collected from African American male Veterans (n = 128).^51^ Two other studies were also conducted at a VA Medical Center and included a total of 644 Veterans.^28,54^ The OSTA study was composed of Korean men.^55^

Each of the included studies aimed to determine the optimal cutoff for the OST in predicting osteoporosis by DXA for the selected population. Three of the studies utilized whole-body DXA scanning, while 5 of the studies based DXA score on scans of specific skeletal locations (various combinations of the spine, femoral neck, radius, and hip).^28,29,50,52,55^ There was variation across studies in whether a female or male reference population was used to calculate T-scores, and this was not specified in some studies.^28,52^ The prevalence of osteoporosis in the studies ranged from 5.3%^29^ to 24.2 %.^28^ The optimal cutoff of OST ranged from 0.99 to 6 with AUCs for these cutoffs ranging from 0.632 to 0.836. In the study of the OSTA, the predefined cutoff of 0 had a sensitivity of 86.2%, specificity of 49.7%, and AUC of 0.680.

Overall results for this synthesis are presented in Figure 6. A meta-analysis of the 8 studies was performed yielding a summary AUC of 0.71 (95% CI 0.659 to 0.77). A Cochrane’s Q of 21.7 (p=0.003) and I^2^ of 67.8% suggest that there is substantial heterogeneity and variability between the studies contributing to this estimate. This score indicates that the OST possesses acceptable diagnostic accuracy. Sensitivity of the OST was also presented as pooled values across the included studies 81.2% (95% CI 74.6 to 86.4). Specificity estimates were not pooled given substantial heterogeneity (I^2^ 96.4%, Q 195.3, p<0.001).

Two of the studies presented subgroup analyses for age and race/ethnicity. Adler et al 2003 obtained similar results after grouping subjects by age (grouped by decades) and race/ethnicity.^54^ However, Richards identified a different optimal cutoff for OST in predicting osteoporosis among Caucasian men (OST cutoff ≤ 5, sensitivity: 75.4%, specificity: 41.4%) versus African American men (OST cutoff ≤ 6, sensitivity: 70.0%, specificity: 36.4%).^53^ This same author suggested that age may impact the predictability of the OST, with subjects > 65 and an OST cutoff ≤ 2 yielding a sensitivity of 80.0% and a specificity of 52.8% versus subjects ≤ 65 and an OST cutoff ≤7 yielding a sensitivity of 76.2% and a specificity of 39.5%.

Figure 6 OST Tool Compared to Osteoporosis

#### OST Risk Assessment Tool in Patients at Higher Risk

The 1 study not included in the forest plot reported the performance of the OST tool among Veterans with rheumatoid arthritis.^56^ This study did not report an overall AUC. However, at a score of 4 or less, the tool correctly identified 78% of the population with osteoporosis and correctly identified 45% as not having osteoporosis compared to a DXA (ie, sensitivity 78%, specificity 45%).

### QFracture

The QFracture Tool was developed to estimate the risk of major osteoporotic fracture (hip, spine, wrist, or shoulder) or hip fracture over the next 10 years. It was developed and validated utilizing a prospective cohort of over 2 million men (49.8% men) and women aged 30–85 years from multiple UK primary care practices.^32^ It includes many of the same clinical risk factors for osteoporosis as the FRAX risk assessment tool with the addition of fall history and 10 others but does not include BMD. We identified 5 prospective/retrospective cohort studies evaluating the QFracture tool in predicting major osteoporotic fracture and hip fracture.^30,32,40,57,58^ The studies compared the QFracture tool to other risk assessment tools and/or to fracture rates. Three of the studies utilized UK cohorts.^32,57,58^ One study was centered in the US^30^ and another in Israel.^40^ Over 6 million men were included in these studies and men aged 30 to 100 years were included. Four of the 5 studies evaluating the QFracture tool had a low risk of bias^30,32,57,58^ and 1 was at risk of bias.^40^

#### Major Osteoporotic Fracture

These studies all evaluated the QFracture tool in predicting major osteoporotic fracture. The 10-year prevalence of major osteoporotic fracture ranged from 0.6% to 7.6% across the studies.^30,32,57,58^ The QFracture has poor to fair discrimination among the 4 studies evaluating a 10-year prediction of major osteoporotic fracture (AUC 0.640 to 0.739)^30,32,57,58^ (Figure 7). Significant statistical heterogeneity was present (I^2^ 98.2%; Q 166.3). The remaining study found poor discrimination of the QFracture tool in predicting 5-year major osteoporotic fracture risk (AUC 0.686).^40^

Figure 7 QFracture Tool Compared to Major Osteoporotic Fracture

#### Hip Fracture

Each of the 5 studies also evaluated the QFracture tool in predicting hip fracture. The 10-year hip fracture prevalence ranged from 0.2% to 4.2%.^30,32,57,58^ Overall, the QFracture had better discrimination for 10-year prediction of hip fracture compared to major osteoporotic fracture with AUC ranging from 0.690 to 0.875 (Figure 8). Significant statistical heterogeneity was present (I^2^ 97.3%; Q 109.4). The study of 5-year prediction of hip fracture also found excellent discrimination with an AUC of 0.856.^40^

Figure 8 QFracture Tool Compared to Hip Fracture

### Male Osteoporosis Risk Estimation Score (MORES)

The MORES was developed to predict osteoporosis at the total hip specifically among men ≥ 50 years and utilizes age, weight in kg, and history of COPD.^59^ The established cutoff is a score ≥ 6 (out of 20) in predicting osteoporosis (sensitivity 93%, specificity 59%, AUC 0.832). Data from 2,995 men were used to develop and validate the algorithm. Shepherd et al later assessed the MORES in predicting osteoporosis at the vertebra or any site.^60^ The original cross-sectional study of the MORES development and validation^59^ and the secondary study assessing the MORES for these additional sites are included in this review. Two additional cross-sectional studies evaluating the MORES in predicting osteoporosis are also included in this review.^27,61^ BMD obtained by DXA served as the gold standard for the diagnosis of osteoporosis in each of the studies for MORES. T-scores were calculated according to varying reference populations across the studies. All 4 studies were conducted in the US and included predominantly white males (76%–88.5%) with mean ages of 63 to 70.2 years. A total of 7,823 men were included in these 4 studies.

#### Osteoporosis

The included studies evaluated the MORES in predicting osteoporosis by DXA. Two studies were low risk of bias^60,61^ and 2 were at risk.^27,59^ The prevalence of osteoporosis across studies ranged from 4.3% to 12.4%. Three of the 4 studies assessed for osteoporosis at the hip.^27,59,61^ One study assessed for osteoporosis at any site (hip or vertebral) and vertebral only. Data from all 4 studies (excluding the validation cohort in 1 study^59^ and the vertebral osteoporosis only outcome in another study^60^) were combined in a meta-analysis. Individually, these studies found the MORES to have fair to excellent discrimination in predicting osteoporosis (AUC 0.728 to 0.870) (Figure 9). Significant statistical heterogeneity was present (I^2^ 91.3%; Q 34.4). The study with the lowest AUC^60^ in the plot was the study evaluating the prediction of osteoporosis at any site (hip or vertebral) versus osteoporosis at the hip only among the 3 other studies.

Among the data not included in the plot, the data from the validation cohort of 1 study^59^ had a similar reported AUC of 0.842 (95% CI 0.811 to 0.873) whereas the data from the vertebral osteoporosis only outcome had poor discrimination with AUC of 0.657.^60^ None of the identified studies evaluated the MORES tool for MOF or hip fracture.

Figure 9 MORES Tool Compared to Osteoporosis

The Garvan model was developed by the Dubbo Osteoporosis Epidemiology Study (DOES) that began in 1989. It predicts the 10-year absolute risk of hip fracture or major osteoporotic fracture. They compared over 50 risk factors and determined that 5 risk factors^62^ accounted for the greatest portion of the variance of risk. The 5 risk factors are: age, bone mineral density, body weight, history of prior fracture after the age of 50, and any falls during the past 12 months.^62^ Four studies^30,40,43,63^ evaluated the Garvan model. Three were both low risk of bias cohort studies; 1 was conducted in Israel,^40^ 1 in Australia,^43^ and the other in the United States, called MrOS.^30^ The MrOS had 5,200 men aged 65 years and older, and the study conducted in Israel had 1,054,815 total participants, of which 478,825 were men ages 50-90. The Nguyen et al cohort study enrolled 2,216 individuals (858 were men) over the age of 60 from the DOES study.^63^ They developed a nomogram to predict a 5-year and 10-year absolute fracture risk.^63^ This at risk of bias study was conducted in Australia and evaluated models with the same risk factors, later known as the Garvan model. We included model II in the review since it did not contain BMD.

#### Major Osteoporotic Fracture

Two studies reported Garvan predicting the risk of MOF.^30,63^ One study had an AUC of 0.66 (95% CI 0.62 to 0.70) reporting p = 0.4517.^30^ The Garvan nomogram study had an AUC of 0.739 with a SE of 0.024 and reporting p = 0.0240 for predicting a 5- or 10-year risk of major osteoporotic fracture in men showing fair discrimination.^63^

#### Hip Fracture

Three studies^30,40,43^ evaluated the Garvan tool and found fair to good discrimination in predicting the 10-year risk of hip fracture. Gourlay et al reported fair discrimination in predicting a 10-year risk of fracture with an AUC of 0.71 (95% CI 0.67 to 0.74)^30^ and Dagan et al found good discrimination in predicting 10-year risk of fracture with an AUC of 0.765.^40^ Holloway-Kew et al reported a similar AUC of 0.773 (95% CI 0.691 to 0.855).^43^ In the tools assessed, the AUC discrimination improved when predicting hip fracture compared to the tools predicting a major osteoporotic fracture.

### Other Clinical Risk Assessment Tools

In addition to the previously described tools, we identified 6 studies^28,55,64–67^ describing 6 additional tools including the FRActure Health Search (FRA-HS) score, Fracture Risk Calculator (FRC), KORAM-M, VA-FARA, Mscore, and the Korean Fracture Risk Score (KFRS). These tools are less common and are described by 2 or fewer included studies.

First, the FRA-HS was developed and validated by Francesco et al for use in primary care settings in Italy. It is a FRAX-based tool^64^ to calculate the 10-year predicted risk of osteoporotic fracture. The FRA-HS consists of the risk factors: BMI, sex, age, long-term use of corticosteroids, alcohol abuse or alcohol-related diseases, smoking status, rheumatoid arthritis, history of osteoporotic fractures, and other causes of secondary osteoporosis. It was a cohort study with a low risk of bias rating that included 407,771 total participants, of which 183,308 were men 40 years or older.

Second, the Fracture Risk Calculator (FRC) was based on the National Osteoporosis Foundation’s selection of key risk factors.^66^ The FRC provides a 10-year risk estimate of both hip fracture and major osteoporotic fracture (ie, hip, clinical spine, forearm, shoulder). Ettinger et al^66^ compared the FRC with and without BMD to see if BMD would affect the performance of the tool. The FRC consists of the risk factors: age, sex, race/ethnicity, BMI, BMD, history of fracture, parental history of hip fracture, smoking and alcohol consumption, use of corticosteroids, the prevalence of rheumatoid arthritis, and secondary osteoporosis. This low risk of bias cohort study was conducted in the United States with 5,893 men aged 65 years and older.

Third, the KORAM-M was developed and validated by Oh et al to identify Korean men at high risk of developing osteoporosis based on the nationwide dataset.^55^ They evaluated 3 models: Model 1 consisted of age and weight; Model 2 age, weight, and health behavior; Model 3 age, weight, exercise, and blood tests. This low risk of bias cross-sectional study was conducted in South Korea and selected 2,450 men 50 years and older.

Fourth, Williams et al compared the performance of 4 tools: FRAX, e-FRAX, OST, and the VA-FARA.^28^ The VA-FARA (Veterans Affairs Fracture Absolute Risk Assessment tool) was designed to identify the risk of fracture as correlated with osteoporosis. The risk factors the VA-FARA consisted of were prior fracture, age > 80, underweight, malnutrition, opioid exposure, proton-pump inhibitor use, depression diagnosis, stroke, seizure disorder, alcohol abuse disorder, fall risk, and clinic visits in prior year. This low risk of bias cross-sectional study was conducted in the United States from the Salt Lake City VA and consisted of 463 men 70 years and older.

Fifth, the Mscore^67^ was developed by Zimering et al and modeled after SCORE for male Veterans. They compared test characteristics in Caucasians and African Americans. It is a weighted risk index for osteoporosis consisting of the variables age, weight, gastrectomy, emphysema, and prior fractures. This at risk of bias cohort study was conducted in the United States and analyzed a total of 970 men ages 40 years and older. They had a development cohort (n = 639), a validation cohort (n = 197), and an African American cohort (n = 134).

Finally, the Korean Fracture Risk Score (KFRS) was developed and validated by Kim et al as an Asian-specific prediction model.^68^ The score predicts a 7-year risk of osteoporotic fracture and consists of the variables: age, body mass index, recent fragility fracture, current smoking status, high alcohol intake, lack of regular exercise, recent use of an oral glucocorticoid, rheumatoid arthritis, and other causes of secondary osteoporosis. This low risk of bias cohort study included 718,306 total participants, of which 370,255 were men ages 50–90 who were enrolled in the Korean NHIS database. They used both a modeling cohort (n = 185,127) and a validation cohort (n = 185,128).

#### Major Osteoporotic Fracture

There were 4 studies^28,64,66,68^ evaluating how these emerging tools predict MOF; the overall discrimination was found to be poor to fair for all 6 studies. The FRA-HS tool had an AUC of 0.49 (95% CI 0.48 to 0.50) for predicting a 10-year risk of major osteoporotic fracture in men showing poor discrimination.^64^ The FRC had an AUC of 0.66, the KFRS had an AUC of 0.68, and the VA-FARA had an AUC of 0.64 (95% CI 0.58 to 0.70).

#### Hip Fracture

There were 2 studies^64,66^ that evaluated these tools on the prediction of hip fracture rates; the overall discrimination was found to be poor to good for all 5 studies. The FRA-HS tool was found to have poor discrimination for risk of hip fracture in men with an AUC of 0.66 and a 95% CI [0.64–0.68].^64^ The FRC has fair discrimination for risk of hip fracture in men with an AUC of 0.71, a sensitivity of 0.74, and a specificity of 0.57.^66^

#### Osteoporosis

There were 2 studies that evaluated tools on prediction risk of osteoporosis.^55,67^ The Mscore was found to have excellent discrimination for the risk of osteoporosis in men with an AUC of 0.84 and a 95% CI 0.74 to 0.95. The 5-variable Mscore was not tested in the African American cohort. The KORAM-M tool was found to have poor discrimination in identifying the risk of osteoporosis; when using a cutoff ≤ −9 resulted in an AUC of 0.638 (SE 0.019), an AUC of 0.618 (SE 0.020) at a cutoff ≤ −10, and AUC of 0.642 (SE 0.018) at a cutoff of ≤ −12.

Overall, for the emerging tools, the discrimination in AUC was relatively higher when predicting hip fracture rates. Despite the Mscore having excellent discrimination when predicting osteoporosis, the validation cohort had the smallest number of participants (n = 197).

## QUALITY OF EVIDENCE FOR KEY QUESTION 1

The ROB was judged at risk for 18 studies and low risk for 18 studies. Patterns that led to judgments of at risk included: 1) patient selection (n = 11), 2) interpretation of index test (eg, FRAX, OST) (n = 13), 3) interpretation of the reference standard (eg, DXA) (n = 9), and 4) patient flow and timing (n = 12). ROB ratings and assessments for each study are shown in Figures 10 and 11.

Figure 10 Risk of Bias Ratings for the Included KQ 1 Studies

Figure 11 Risk of Bias Assessment Across Included KQ 1 Studies

## KEY QUESTION 2 Among [underlined: male Veterans] not identified by a history of low-trauma fracture, is there a tool or combination of risk factors that identify patients at highest risk of osteoporosis or major osteoporotic fracture?

### Characteristics of Included Studies

To address this question, we evaluated the subset of studies conducted specifically in [underlined: male Veterans] not identified by a history of low-trauma fracture. These studies examined individual risk factors or risk assessment tools and their association with osteoporosis or osteopenia, defined by T-scores on DXA, and fracture defined by diagnosis codes. Some of the studies described in this section have been previously discussed in KQ 1 results above, but here are revisited within the context of Veteran-specific analyses. Specifically, 8 studies appear both in KQ 1 and KQ 2.^26,28,48,51,53,54,56,67^

Eight studies^26,28,48,51,53,54,56,67^(n = 26,469) examined risk assessment tools, and of these, three^26,48,56^ (n = 24,848) were conducted in populations of special interest where fracture risk is considered higher than the general population. Twelve studies^51,69–79^ (n = 585,400) assessed individual risk factors for low BMD and/or fracture and risk factors were broadly categorized as conditions or exposures (eg, smoking, alcohol, medications). Mean age varied across studies, from 55.6 to 80.4 years in studies examining risk tools, and 46 to 76 years in those evaluating individual risk factors. Race/ethnicity of studied populations varied widely, as illustrated in Table 2.

Overall, there was substantial conceptual heterogeneity across studies in terms of: a) which risk factors were utilized in tools; b) how risk factors were obtained (ie, patient report vs obtained from EHR); c) cutoffs used for the same risk prediction tools (ie, non-guideline recommended cutoffs for OST score); and d) how outcomes were defined (eg, diagnosis codes, T-scores). Appendix B summarizes study characteristics. Additionally, when BMD measurements by DXA were utilized to define osteoporosis, the reference population for T-scores varied across studies, and in some cases was not reported (3 studies^28,76,80^).

### KeyKey Points

- Many studies report tools predicting osteoporosis and fracture (n = 8) as well as independent risk factors (n = 12) among male Veteran populations.
- Tools perform similarly [underlined: among male Veterans] compared to other male populations:
  ○ OST/OSTA predicted osteoporosis similarly among Veterans (AUC 0.670 to 0.890) as among general populations (AUC 0.632 to 0.740).
  ○ FRAX had an AUC of 0.72 (95% CI 0.67 to 0.78) for predicting osteoporosis in 1 Veteran study, and AUC 0.596 to 0.870 in general populations.
- Among an average-risk male Veteran population, tools using combinations of risk factors had moderate discriminant validity to predict osteoporosis and/or fracture:
  ○ FRAX and OST were the most common tools used to assess combinations of risk factors for predicting osteoporosis and/or fracture among male Veterans.
  ○ A single study suggests the Mscore may perform well for predicting osteoporosis among male Veterans.
- Tools using combinations of risk factors to predict osteoporosis and/or fracture in [underlined: Veterans at high risk for fracture] had low/moderate discriminant validity:
  ○ Among male Veterans, FRAX appears to underestimate risk of fracture in HIV and HCV infection, as well as in those treated with ADT.
  ○ Compared to its performance in average risk male Veteran populations, OST appears to perform sub-optimally for predicting osteoporosis in male Veterans with rheumatoid arthritis.
- Among male Veterans, we identified limited evidence supporting individual risk factors for osteoporosis and/or fracture. All included studies risk factor studies were at high or unclear risk of bias.

### FindingsDetailed Findings

### Risk Assessment Tools (Using Combinations of Risk Factors) to Predict Osteoporosis and/or Fracture in Male Veterans

We identified eight^26,28,48,51,53,54,56,67^ studies (n = 26,469) that assessed combinations of risk factors for osteoporosis and/or fracture in the form of risk assessment tools specifically among male Veterans (note: all of these studies were also reported above in KQ 1). The most common tools examined were the FRAX (or modified versions of FRAX) and OST. Other tools included VA-FARA and Mscore; however, these were examined in only 1 study each.^28,67^ Three studies^26,48,56^ (n = 24,848) were conducted on populations of special interest who may be at heightened risk of osteoporosis and fracture: (1) human immunodeficiency virus (HIV) and hepatitis C virus (HCV) infection (FRAX)^26^; (2) history of androgen deprivation therapy for localized prostate cancer (FRAX)^48^; and (3) rheumatoid arthritis (OST)^56^. Only 1 study (n = 463) conducted a direct head-to-head comparison of different risk assessment tools,^28^ and this study compared FRAX, OST, and VA FARA using electronic health record (EHR) data from an average risk male Veteran population.

#### FRAX and Modified FRAX Scores

##### Performance in Average Risk Veterans

We found only 1 study that investigated FRAX and a modified FRAX in predicting osteoporosis (T-score ≤ −2.5 on DXA) among 463 male Veterans with no known risk factors for accelerated bone loss.^28^ Their approach to the standard FRAX calculation involved obtaining risk factors through a patient questionnaire. They also examined a modified FRAX score, coined “e-FRAX,” that involved risk factor ascertainment via EHR review. In the e-FRAX tool, parental hip fracture was the only risk factor assumed to be absent since documentation of this is known to be poor in the EHR. FRAX had better accuracy than e-FRAX (AUC 0.72 [95% CI 0.67 to 0.78] vs 0.65 [95% CI 0.59 to 0.71]) for predicting osteoporosis in this study, which may be attributable to a more accurate representation of risk factors when obtained by patient self-report versus EHR extraction. Given that few studies evaluating FRAX in Veteran populations used similar estimates (ie, AUC, sensitivity, specificity), our ability to draw comparisons to non-Veteran populations is limited. However, they seem to perform similarly (AUC 0.596 to 0.870 in general populations). The majority of Veterans in this study were Caucasian (94.2%), so additional data would be needed to understand the performance of FRAX ad e-FRAX in a racially diverse male Veteran population.

##### Performance in Veterans at Higher Risk

[underlined: HIV infection]: In the study by Yin et al^26^ that examined a modified FRAX score in male Veterans with and without HIV infection (n = 24,451), FRAX (not including BMD, and assuming low risk of parental hip fracture) underestimated true fracture risk with a goodness-of-fit observed/expected (O/E) ratio for MOF of 1.39 (95% CI 1.30 to 1.48) in the total cohort, and lower accuracy for those with HIV infection (O/E of 1.62, 95% CI 1.45 to 1.81). While inclusion of HIV as a cause of secondary osteoporosis (“yes” in FRAX) improved its accuracy in predicting MOF (O/E 1.20) in HIV infection, it still underestimated risk in this population. As seen in Table 3, even when HIV was included as a cause of secondary osteoporosis, FRAX was a poor predictor of hip fracture among male Veterans with (O/E 2.66) and without (O/E 3.56) HIV infection. Overall, these data suggest modified FRAX (without BMD) underestimates fracture risk in HIV. It is worth noting that sensitivity for detecting MOF and hip fractures were very low in this study, both in HIV infected and uninfected populations. Specifically, sensitivity for detecting fracture was only 0 to 6.4% using accepted FRAX thresholds for initiating osteoporosis care. It is possible that younger age of Veterans (mean = 55.6 years) contributed to this finding, given mean age was substantially different than other studies we identified (although FRAX is validated in ages 40–60), or that EHR-based ascertainment of certain FRAX components (eg, smoking, alcohol) limited its performance in this population. Also, this study included a more racially diverse population than Williams et al, with 46.3% and 8.7% Veterans identifying as Black race or Hispanic ethnicity, respectively. There may be differences in the ability of FRAX to predict fracture across races and ethnicities; however, current data are limited in this regard and no conclusions can be drawn.

[underlined: HCV infection and HCV/HIV co-infection]: Yin et al^26^ also examined the performance of modified FRAX (without BMD) in predicting fracture among male Veterans with HCV infection, regardless of HIV status. As detailed in Table 3, when patients with HCV infection—without HIV—were assumed to have secondary osteoporosis in the modified FRAX, the accuracy of the tool for predicting MOF (O/E 1.27) was similar to that seen in the HIV population with or without HCV infection (O/E 1.20). The risk of MOF was also underestimated by modified FRAX in the HCV/HIV co-infected population (O/E 1.48); it was likewise a poor predictor of hip fracture among male Veterans with HCV infection, independent of HIV status (O/E for HIV+ 3.87, O/E for HIV− 3.44).

[underlined: Androgen deprivation therapy (ADT)]: Another population of special interest examined by FRAX was male Veterans who had undergone ADT, a known risk factor for accelerated bone loss.^48^ Of 115 patients in this study (60% African American), 54% met standard thresholds for FRAX (10-year risk of ≥ 20% for MOF or ≥ 3% of hip fracture), and only 33% had a T-score in the osteoporosis range via DXA. The proportion of Veterans with osteoporosis who were captured by these FRAX thresholds is unclear based on available data. Authors calculated a “FRAX” T-score by using the FRAX patch, which was available through the National Osteoporosis Foundation (NOF) website. Comparison of the “FRAX” T-score (mean −0.4 (±1.5) to BMD at the forearm (–1.2, ±1.9) and hip (–1.4, ±1.1) suggests that FRAX underestimates the risk of osteopenia and/or osteoporosis at these sites in men treated by ADT. In contrast, the “FRAX” T-score approximated BMD at the spine (0.0, ±1.8), although this site is known to be less predictive of fracture in men as compared to women.^81–83^ While far from definitive, these data suggest that FRAX underestimates osteoporosis at the wrist and hip in men treated with ADT.

#### OST

##### Performance in Average Risk Veterans

Three studies^28,53,54^ (n = 1,162) examined OST with the intent of evaluating its performance in a community-dwelling male Veteran population. OST predicted osteoporosis similarly among general populations (AUC 0.632 to 0.740) as among Veterans (AUC 0.670 to 0.890). Williams et al^28^ found an OST score below 1 to predict osteoporosis by DXA with a sensitivity of 69% and specificity of 60% (AUC 0.71, 95% CI 0.65 to 0.76). The same cut-off of 1 in Adler et al^54^ had higher sensitivity (75%) and specificity (80%) for identifying osteoporosis (AUC 0.84, 95% CI 0.75 to 0.92), and sensitivity increased substantially (93%) when an OST cut-off of 3.0 was used. Last, Richards et al found an OST score below 6 to have good sensitivity (82.6%), but a much lower specificity (33.6%) (AUC 0.67, 95% CI NR).^53^ There are important differences between these 3 study populations that may account for variation in the predictive ability of OST. Williams et al (n = 463) and Richards et al (n = 518) enrolled Veterans from the general medicine setting (and had similar AUC of 0.67 to 0.71), and Adler et al recruited a smaller cohort (n = 181) of Veterans from pulmonary and rheumatology clinics, where the risk of osteoporosis was likely higher. While Adler et al^54^ found that OST performed similarly in patients with (AUC 0.79, 95% CI NR) and without (AUC 0.80, 95% CI NR) current glucocorticoid use, they did not examine the role of prior glucocorticoid exposure or the presence of inflammatory conditions that were likely driving heightened osteoporosis risk in this population. One study^53^ noted OST to have a better predictive ability in non-Hispanic Caucasian (AUC 0.72, 95% CI NR) versus African American (AUC 0.58, 95% CI NR) Veterans, and in older age groups (ie, > 65 years of age). While another study noted especially high AUC (0.99) in Veterans aged ≥ 80 years, there was no consistent trend observed in OST performance across age subgroups.^54^ Likewise, no notable differences across racial/ethnic subgroups were noted in 2 of 3 studies,^28,54^ even though only 1 had a sufficient African American population (25.1% of total cohort) to examine this association (ie, Williams et al study was 94.2% Caucasian). With the exception of 1 study where the reference population was not reported,^28^ all studies examining OST utilized the male reference population from NHANES III to define osteoporosis at the hip. See Table 3 for additional detail on these studies.

A separate study focused on the performance of OST in an African American population. Sinnott et al^51^examined 128 African American male Veterans recruited from general medicine clinics and found OST to perform reasonably well at a cut-off of 4, with a sensitivity of 89% and specificity of 54% for detecting osteoporosis (AUC 0.89, 95% CI 0.75 to 1.03). Although African American males have traditionally been considered a low-risk group for osteoporosis, a prevalence of 7% was noted in this study; this is unexpectedly high, but it may still be an underestimation, given a Caucasian male normative database (NHANES III) was used for the hip, and Caucasian men are known to have lower BMD than African American men.

##### Performance in Veterans at Higher Risk

One study^56^ examined the performance of OST in 282 male Veterans with rheumatoid arthritis, and a score below 4 predicted osteoporosis with a sensitivity of 78% and specificity of 45% (AUC not reported).

Table 3 FRAX, Modified FRAX and OST for Assessing Risk of Osteoporosis and/or Fracture in Male Veterans

Study; Risk assessment tool; (Tool components) | N with outcome; Total n; (Condition-specific population) | Outcome metric (definition); Reference population | Sens & Spec; (Threshold) | AUC (95% CI) | ROB
Williams, 2017^28^; e-FRAX; FRAX adapted to EHR (age, sex, weight, height, previous fracture, parental hip fracture, smoking, glucocorticoid treatment, rheumatoid arthritis, alcohol intake) | Osteoporosis: 112; Total n = 463 | Osteoporosis (T-score ≤ −2.5); NR | Sens 0.688; Spec 0.544; (≥ 20 % risk for MOF; ≥ 3 % risk for hip fracture) | AUC/ROC 0.65 (0.59 to 0.71) | Low risk of bias
Williams, 2017^28^; FRAX; (age, sex, weight, height, previous fracture,parental hip fracture, smoking, glucocorticoid treatment, rheumatoid arthritis, alcohol) | Osteoporosis: 112; Total n = 463 | Osteoporosis (T-score ≤ −2.5); NR | Sens NR; Spec NR; (NOF and ACR) FRAX : ≥ 3% for hip fracture; ≥ 6.5% for major osteoporotic fractures | AUC/ROC 0.72 (0.67 to 0.78) | Low risk of bias
Yin, 2016^26^; Modified FRAX (total, HIV+, HIV−) | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Major osteoporotic fracture rate defined by ICD9 codes | NR; NR | Observed/expected: total 1.39 (95% CI 1.30 to 1.48); HIV− 1.29 (95% CI 1.19 to 1.40); HIV+ 1.62 (95% CI 1.45 to 1.81); p-value for difference between HIV+ vs HIV− O/E 0.03 | At risk of bias
Yin, 2016^26^; Modified-FRAX calculated with HIV as secondary osteoporosis | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Major osteoporotic fracture rate defined by ICD9 codes | NR; NR | Observed/expected: HIV− 1.29 (95% CI 1.19 to 1.40); HIV+ 1.20 (95% CI 1.08 to 1.34) | At risk of bias
Yin, 2016^26^; Modified-FRAX (total, HIV infected, HIV−) | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Hip fracture rate defined by ICD9 codes | NR; NR | Observed/expected hip fracture: total 3.87 (95% CI 3.42 to 4.40); HIV− 3.56 (95% CI 3.03 to 4.18); HIV+ 4.52 (95% CI 3.68 to 5.53) | At risk of bias
Yin, 2016^26^; Modified-FRAX calculated with HIV as secondary osteoporosis (HIV+, HIV−)^b^ | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Hip fracture rate defined by ICD9 codes | NR; NR | Observed/expected: HIV− 3.56 (95% CI 3.03 to 4.18); HIV+ 2.66 (95% CI 2.17 to 3.26) | At risk of bias
Yin, 2016^26^; Modified-FRAX calculated with HIV as secondary osteoporosis: HIV+ | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Major osteoporotic fracture rates defined by ICD9 codes | Sens 6.4%; Spec 98.6%; (Since none met the NOF fracture threshold of > 20%, the age-specific thresholds endorsed by European osteoporosis societies was utilized [6.3% to 13.4% in 50- to 70-year-olds]) | NR | At risk of bias
Yin, 2016^26^; Modified-FRAX calculated with HIV as secondary osteoporosis: HIV− | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Major osteoporotic fracture rates defined by ICD9 codes | Sens 2.6%; Spec 99.5%; (Since none met the NOF fracture threshold of > 20%, the age-specific thresholds endorsed by European osteoporosis societies was utilized [6.3% to 13.4% in 50- to 70-year-olds]) | NR | At risk of bias
Yin, 2016^26^; Modified-FRAX calculated with HIV as secondary osteoporosis: HIV+ | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Hip fracture rate defined by ICD9 codes | Sens 3.2%; Spec 99.0%; (FRAX: ≥3 % for hip fracture probability) | NR | At risk of bias
Yin, 2016^26^; Modified-FRAX calculated with HIV as secondary osteoporosis: HIV− | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Hip fracture rate defined by ICD9 codes | Sens 0%; Spec 99.9%; (FRAX: ≥3 % for hip fracture probability) | NR | At risk of bias
Yin, 2016^26^; Modified-FRAX calculated with HCV as cause of secondary osteoporosis: HIV+ | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Major osteoporotic fracture rate defined by ICD9 | NR | Observed/expected: 1.48 (1.33 to 1.65) | At risk of bias
Yin, 2016^26^; Modified-FRAX calculated with HCV as cause of secondary osteoporosis: HIV− | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Major osteoporotic fracture rate defined by ICD9 | NR | Observed/expected: 1.27 (1.17 to 1.37) | At risk of bias
Yin, 2016^26^; Modified-FRAX calculated with HCV as cause of secondary osteoporosis: HIV+ | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Hip fracture rate defined by ICD9 | NR | Observed/expected: 3.87 (3.16 to 4.75) | At risk of bias
Yin, 2016^26^; Modified-FRAX calculated with HCV as cause of secondary osteoporosis: HIV− | MOF HIV−: 609; MOF HIV+: 326; Hip HIV−: 148; Hip HIV+: 93; Total n = 24451; (HIV+ n = 7064; HIV− n = 17387) | Hip fracture rate defined by ICD9 | NR | Observed/expected: 3.44 (2.93 to 4.04) | At risk of bias
Adler, 2010^48^; FRAX; (age, sex, weight, height, previous fracture, parental hip fracture, smoking, glucocorticoid treatment, rheumatoid arthritis, alcohol) | Osteoporosis: 33%; Total n = 115; (Androgen deprivation therapy) | Osteoporosis (T-score ≤ −2.5); NHANES III (male) | Sens NR; Spec NR; FRAX: ≥ 20 % risk for major osteoporotic fracture or ≥ 3% risk for hip fracture | 54% had a FRAX probability above 20% for MOF or 3% for hip fracture^b^; 35% had a T-score ≤ −2.5 measured with DXA^b^ | Low risk of bias
Williams, 2017^28^; OST; (Age, Weight) | Osteoporosis: 112; Total n = 463 | Osteoporosis (T-score ≤ −2.5); NR | Sens .688; Spec .598; (OST score <0.99) | AUC/ROC 0.71 (0.65 to 0.76 | Low risk of bias
Richards, 2014^53^; OST; (Age, Weight) | Osteoporosis: 92; Total n = 518 | Osteoporosis (T-score ≤ −2.5); NHANES III (male) | Sens 82.6%; Spec 33.6%; (OST score ≤ 6) | AUC/ROC 0.67 | At risk of bias
Sinnott, 2006^51^; OST; (Age, Weight) | Osteoporosis: 7%; N = 128 | Osteoporosis (T-score ≤ −2.5); Caucasian male normative database for the hip and the manufacturer’s female spine database | Sens 89; Spec 54; (OST score 4) | AUC/ROC 0.89 (95% CI 0.75 to 1.03) | At risk of bias
Richards, 2009^56^; OST; (Age, Weight) | Osteoporosis: 50; Total n = 282 (Rheumatoid arthritis) | Osteoporosis (T-score ≤ −2.5); NHANES III (male) | Sens 78; Spec 45; (OST score ≥ 4) | NR | At risk of bias
Richards, 2009^56^; OST; (Age, Weight) | Osteoporosis: 50; Total n = 282 (Rheumatoid arthritis) | Osteoporosis (T-score ≤ −2.5); NHANES III (male) | Sens 6; Spec 94; (OST ≤ −2) | NR | At risk of bias
Richards, 2009^56^; OST; (Age, Weight) | Osteoporosis: 50; Total n = 282 (Rheumatoid arthritis) | Osteopenia (T-score between −1.0 and −2.5); NHANES III (male) | Sens 64; Spec 54; (OST ≤ 4) | NR | At risk of bias
Adler, 2003^54^; OST; (Age, Weight) | Osteoporosis: 15.6%; Total n= 181 (Pulmonary or rheumatology clinic population) | Osteoporosis (T-score ≤ −2.5); NHANES data for hip, Hologic reference source for spine | Sens 93; Spec 66; (OST score 3) | AUC/ROC 0.836 | At risk of bias
Adler, 2003^54^; OST; (Age, Weight) | Osteoporosis: 15.6%; Total n= 181 (Pulmonary or rheumatology clinic population) | Osteoporosis (T-score ≤ −2.5); NHANES data for hip, Hologic reference source for spine | Sens 82; Spec 74; (OST score 2) | AUC/ROC 0.836 | At risk of bias
Adler, 2003^54^; OST; (Age, Weight) | Osteoporosis: 15.6%; Total n= 181 (Pulmonary or rheumatology clinic population) | Osteoporosis (T-score ≤ −2.5); NHANES data for hip, Hologic reference source for spine | Sens 75; Spec 80; (OST score 1) | AUC/ROC 0.836 | At risk of bias

a HIV+ are people living with HIV and HIV− are people not identified as living with HIV.

b Exact percentages obtained via correspondence with the author.

#### Mscore

Mscore was assessed in 1 study^67^ of male Veterans who were recruited primarily from general medicine clinics, and to a lesser extent, endocrinology and osteoporosis clinics. They found an Mscore cut-off of 9 predicted osteoporosis (T-score on DXA ≤ −2.5) with 88% sensitivity and 57% specificity (AUC 0.84, 95% CI 0.74 to 0.95) in the validation cohort of Caucasian male Veterans (n = 197). The same cut-off in a reduced version of Mscore including only age and weight yielded similar sensitivity and specificity, 85% and 58% respectively (AUC 0.81, 95% CI 0.69 to 0.92). The reduced Mscore performed even better in a validation cohort of African American Veterans (n = 134), with a sensitivity as high as 93%, a specificity of 79%, and an AUC of 0.89 (95% CI 0.79 to 0.98) when race-specific reference data (NHANES III) were used (AUC 0.99, 95% CI 0.98 to 1.01, if Caucasian reference data used). Combined with the robust performance of OST in this study, these data suggest age and weight may be the most influential clinical variables in risk assessment tools for osteoporosis, and that the 5-variable Mscore may be more complex than necessary to assess risk of osteoporosis in male Veterans.

#### VA-FARA

One study^28^ examined the use of VA-FARA in 463 male Veterans. Similar to FRAX, VA-FARA calculates 10-year probabilities of MOF and hip fracture. Using the same cut-offs as FRAX for these outcomes (see Table 4), Williams et al found it had a sensitivity of 64.3% and specificity of 58.4% for predicting osteoporosis (AUC 0.64, 95% CI 0.58 to 0.70). It suffers from similar drawbacks as with e-FRAX noted above (whose AUC was similar at 0.65 [95% CI 0.59 to 0.71]), as it relies on EHR data that may not be accurate or complete. Furthermore, it does not appear to outperform simpler tools, such as OST or the reduced Mscore.

Both Mscore and VA-FARA are “homegrown” tools examined in 1 study each^28,67^ (as with e-FRAX described above), so while Mscore appears to better predict osteoporosis than VA-FARA, there are insufficient data to recommend 1 of these approaches over another or to recommend any of these tools above FRAX and OST that have been studied and validated across broader populations.

Table 4 Studies Examining Mscore and VA-FARA as One-off Tools to Predict Osteoporosis and/or Fracture in Male Veterans

Study; Risk Assessment tool; (Tool components) | N with outcome; Total n; (Condition-specific population) | Outcome metric (definition); Reference population | Sens & Spec; (Threshold) | AUC/ROC (95% CI) | ROB
Zimering, 2007^67^; Mscore; (Age, weight, gastrectomy, emphysema, 2 or more prior fractures) | Osteoporosis in validation cohort: 11%; Validation group 1 n = 197 | Osteoporosis (T-score ≤ −2.5); NHANES III Male | Sens 88; Spec 57; (MSCORE of 9) | AUC/ROC 0.84 (NR) | At risk of bias
Zimering, 2007^67^; Mscore; (Age, weight) | Osteoporosis in African American validation group: 11%; African American validation group n = 134 | Osteoporosis (T-score ≤ −2.5); NHANES III Male (race-specific) | Sens 93; Spec 79; (Mscore of 9) | AUC/ROC 0.89 (95% CI 0.79 to 0.98) | At risk of bias
Zimering, 2007^67^; Mscore; (Age, weight) | Osteoporosis in Caucasian validation cohort: 11%; Validation group 1 n = 197 | Osteoporosis (T-score ≤ −2.5); NHANES III Male (race-specific) | Sens 85; Spec 58; (Mscore of 9) | AUC/ROC 0.81 (95% CI 0.69 to 0.92) | At risk of bias
Williams, 2017^28^; VA-FARA; (Prior fracture, age > 80, weight, DM complications, malnutrition, CVA, smoking, EtOH, 6–12 clinic visits, 13+ clinic visits in prior year, fall risk) | Osteoporosis: 112; Total n = 463 | Osteoporosis (T-score ≤ −2.5); NR | Sens .643; Spec .584; (≥ 3% for hip fracture; ≥ 20% for major osteoporotic fractures) | AUC/ROC 0.64 (0.58 to 0.70) | Low risk of bias

### Assessment of Individual Risk Factors

Of the 12 studies^51,69–79^ that examined individual risk factors for low BMD and/or fracture among male Veterans (n = 585,400), 9 studies^51,69,71,73,75–79^ exclusively examined the role of medical conditions as risk factors (ie, HIV infection, osteomyelitis, elevated BMI, chronic kidney disease, vitamin D deficiency, chronic pancreatitis), while the remaining studies assessed exposures (eg, medication use), or combinations of conditions and exposures in specific Veteran populations. These are summarized in Table 5. Overall, there was a high level of heterogeneity in terms of: a) how risk factors were defined; b) the level of detail regarding these risk factors; c) populations in which risk factors were studied; d) outcomes; and e) how effect sizes were calculated and reported across studies (eg, odds ratios, hazard ratios, correlation coefficients, F-statistic).

#### Studies of Medical Conditions as Risk Factors

##### Osteomyelitis, HIV infection and HIV-associated factors in the VA Aging Cohort Study (VACS)

Four studies examined risk factors for fracture using data from the VACS that includes Veterans with HIV infection (+/− HCV infection), as well as age- and race-matched Veteran controls without HIV infection.^71,75,77,79^

One study^71^ investigated the risk of fragility fracture in male Veterans with and without osteomyelitis, and after adjusting for demographic and clinical variables (including steroid use, 9 of the 11 FRAX variables, as well as HIV, HCV, and diabetes status), they found presence of osteomyelitis to be associated with highest odds of vertebral fracture (aOR 2.43, 95% CI 1.17, 5.03), followed by upper arm/humerus fracture (aOR 1.95, 95% CI 1.02, 3.74) and fracture at any site (aOR 1.65, 95% CI 1.15, 2.36); no significant association was noted with hip fracture. A sensitivity analysis excluding patients with pelvic or lower extremity osteomyelitis was conducted as a means of accounting for fall risk related to osteomyelitis at these sites and similar results were noted. Another potential source of confounding is the exclusion of nearly half of male Veterans aged 50–70 from this database due to incomplete data for fracture-associated variables; the eligible cohort decreased to 24,251 from 42,924 due to incomplete data. Lack of understanding of how this population differed from the analytic cohort in terms of osteomyelitis and fracture risk limits conclusions that can be drawn.

One study^77^ utilizing VACS data examined HIV infection as a risk factor for fragility fracture (composite of hip, spine, humerus) in male Veterans (n = 40,115). While they found HIV to predict fracture, (aHR 1.24, 95% CI 1.11 to 1.39), this was not significant after adjusting for BMI in multivariable analysis. This may suggest that maintenance of weight and nutritional status is protective against fracture among male Veterans with HIV infection. To explore how HIV severity and care factors may impact fracture risk, another study^75^ in this cohort examined how a “VACS index” score and its individual components related to fracture risk in HIV infection. The VACS index includes demographic, clinical, and laboratory data, as well as HIVspecific variables such as CD4 count, HIV viral load, and use of antiretroviral medications relevant to bone health, specifically tenofovir, protease inhibitors, and efavirenz. A higher VACS index approximates frailty in male Veterans with HIV infection and predicts mortality.^84–86^ Notably, this study found only a modest association between the VACS index and fragility fracture (aHR 1.15, 95% CI 1.11 to 1.19) – this was also true of the individual components of the index, including use of antiretroviral therapies that may have direct effects on bone quality (tenofovir, protease inhibitors) or raise the risk of falls through central nervous system effects (efavirenz). Increasing age appeared to be the most potent risk factor for fragility fracture in this population (aHR for age by 10-year increments, 1.40, 95% CI 1.27 to 1.54), not unlike populations without HIV infection.

Another study evaluated the VACS Index and risk of low BMD among HIV-positive Veterans.^79^ The VACS Index score was found to be significantly associated with the risk of low BMD (ie, osteopenia or osteoporosis by DXA) in HIV-positive Veterans, with the odds of low BMD increasing 1.21 times for every 10 unit increase in VACS index score. However, as per Womack et al (a much larger cohort),^77^ a higher VACS score may not necessarily translate to increased fracture risk.

##### Weight (kg) and body mass index (BMI)

In a cohort of 128 African American male Veterans with average BMI in the overweight range (28.9 kg/m^2^), weight below 85kg was found to predict low BMD with a sensitivity of 74% and specificity of 50%.^51^ Specifically, weight (< 85kg) predicted osteoporosis (T-score ≤ −2.5) with an AUC of 0.75 (95% CI 0.57 to 0.92), and unexpectedly, BMI was not as predictive (AUC 0.67, 95% CI 0.47 to 0.87).

##### Chronic kidney disease (CKD)

One study examined the association between different CKD stages and the risk of fracture.^73^ Of the 712,918 male Veterans in this study, the vast majority (95.2%) had CKD stage 3. CKD stages 4 and 5 accounted for 4.3% and 0.5% of the cohort, respectively. The outcome of fracture included any site, and 22.6% of all fractures in this study occurred in the rib or clavicle, which are not sites of fragility that define clinical osteoporosis. However, most other fractures occurred in either the hip/femur (25.8%) or vertebra (16.9%). A critical finding of this study is the importance of accounting for mortality in CKD populations, as the authors noted that the association between CKD and fracture was no longer significant after accounting for death as a competing event in this male Veteran population. The only exception was for CKD stage 3, where there was a modestly elevated OR of 1.07 (95% CI 1.02 to 1.11) for predicting fracture, even after adjusting for mortality. Age and race did not moderate the effects of CKD on fracture in this study.

##### Vitamin D deficiency

Vitamin D^78^ is a critical contributor to bone metabolism and its deficiency, as defined by a 25-hydroxy vitamin D level < 15 ng/mL, was explored as a risk factor for low BMD in 1 study of 112 African American male Veterans. Prevalence of osteoporosis by T-scores (as per WHO criteria) was similar in Veterans with (3.5%, n = 58) and without (3.7%, n = 54) vitamin D deficiency. In contrast, osteopenia was more prevalent in patients without vitamin D deficiency (25.9%) as compared to those with vitamin D deficiency (19%). In this study, the authors noted no correlation between vitamin D level and BMD (g/cm^2^).

##### Chronic pancreatitis

Chronic pancreatitis is relevant to bone health because exocrine deficiency from pancreatitis may lead to malabsorption of nutrients (including vitamin D) and a heightened risk of fracture.^69^ In a retrospective analysis of 3,257 male Veterans diagnosed with chronic pancreatitis, 4.7% (n = 153) sustained a fracture at any site over a 10-year period. Notably, Veterans were identified as having chronic pancreatitis by diagnosis code, which has been shown to have a sensitivity of 87% and specificity of 86% in VA databases.^87^ When compared to an unmatched control population of similar age (~54 years) but without chronic pancreatitis, the presence of chronic pancreatitis was associated with significantly higher odds of hip fracture (aOR 2.69, 95% CI 2.13 to 3.40), followed by fracture at any site (OR 1.73, 95% CI 1.46 to 2.05) and vertebral fracture (aOR 1.56, 95% CI 1.06 to 2.31). No significant impact was noted on the risk of wrist fracture. Authors adjusted for age and etiology of pancreatitis (alcohol, smoking, or both) in multivariable analysis, but did account for race/ethnicity, medication use (eg, use of proton pump inhibitors, steroids, bisphosphonates), severity of pancreatic disease, or aspects of chronic pancreatitis treatment.

##### Post-traumatic stress disorder (PTSD)

Veterans who have been prisoners of war (POW) may have multiple risk factors for bone loss related to captivity, including dietary deficiencies, vitamin D deficiency, and immobility. Evidence suggests that repatriation of POW is associated with reversal of bone loss in most cases^88^; however, the burden of PTSD remains high in this population. One study^76^ evaluated the effect of PTSD by comparing BMD of repatriated POW with (n = 61) and without (n = 180) PTSD, and a control group (n = 79) of combat-experienced, non-POW Veterans without PTSD. The mean age was 62.2–63.4 years in this study, and mean captivity duration for repatriated POW (regardless of PTSD status) was 53 months. Estimated weight loss was similar between POW, regardless of PTSD status (PTSD+ 44.5 lbs; PTSD− 43.6 lbs). Despite noting a significant difference across groups in terms of hip T-scores (lower in POW PTSD+ vs POW PTSD− and control group), a similar pattern was not noted for spine T-scores, and all Veterans had T-scores in the “normal” range (ie, > −1.5). Furthermore, while age, BMI, ethnicity, and alcohol use were adjusted for in the model, smoking status was not accounted for. It is plausible that smoking elevated the risk for bone loss in POW with PTSD as their tobacco exposure by pack-years was notably higher than the other 2 groups (21 pack-years vs 16 to 17 pack-years).

#### Exposures or Combinations of Medical Conditions and Exposures as Risk Factors

##### Thyroid cancer and levothyroxine supplementation

In the setting of thyroid cancer, high doses of thyroid hormone (levothyroxine) are purposefully given to suppress TSH and limit growth of cancer cells.^70^ High levels of thyroid hormone increase bone turnover and promote bone loss, and in non-Veteran populations, an association has been noted between treatment of thyroid cancer (with high levothyroxine doses) and osteoporosis.^89,90^ One case-control study examined this association among male Veterans by comparing osteoporosis and fracture rates (defined by diagnosis codes) in patients with and without thyroid cancer, matched for age, sex, weight, and steroid use. Both cases (thyroid cancer) and controls (hypothyroidism) were on levothyroxine therapy, however, Veterans with thyroid cancer were being treated to lower TSH goals as part of their management of thyroid cancer, whereas controls were treated to euthyroidism. The odds of being assigned an osteoporosis diagnosis were higher among Veterans with thyroid cancer versus controls (OR 1.46, 95% CI 1.26 to 1.68). For unclear reasons, diagnosis of fracture was significantly lower in thyroid cancer cases versus controls (OR 0.70, 95% CI 0.58 to 0.85). The authors did not observe a difference between groups in receipt of osteoporosis medications in their multivariable model. These data are limited by uncontrolled confounders (eg, smoking, alcohol), and since the prescription of high-dose levothyroxine was likely to have prompted providers to screen for osteoporosis, ascertainment bias is highly likely to have influenced these results.

##### Ulcerative colitis and risks related to malnutrition, vitamin D deficiency, steroid use, and others

Several studies in non-Veteran populations have identified inflammatory bowel disease (including ulcerative colitis) as a risk factor for low BMD and fractures.^91^ One nationwide VA study assessed individual risk factors for low BMD and fracture among 34,665 Veterans with ulcerative colitis; diagnosis codes were used to define outcomes of osteopenia and osteoporosis (collectively defined as “low BMD” in this study) and fragility fracture.^74^ Risk factors were also defined by diagnosis codes, except for prednisone use that required pharmacy data. The presence of tobacco abuse, malnutrition, vitamin D deficiency, and high prednisone exposure (> 11,136 mg over a 10-year period) were associated with higher risk of both low BMD and fragility fracture among male Veterans. High prednisone exposure was strongly linked to low BMD (OR 8.9, 95% CI, 7.8 to 10.2) and appeared to follow a predictable dose-response trend, whereas it was associated with fracture to a lesser extent (OR 1.8, 95% CI 1.3 to 2.5) and ORs did not consistently increase with greater prednisone exposure. It is also important to note that this study included osteopenia in the outcome of low BMD, which may have weakened the relationship with examined risk factors.

#### Antipsychotic Drugs

Use of antipsychotic medications may lead to hyperprolactinemia, which can cause hypogonadism, a known risk factor for bone loss. They may also contribute to orthostatic hypotension and fall risk. We identified 1 study that examined the association between antipsychotic use (≥ 3 months over 10-year period) and fracture rates in a predominantly male Veteran population (91% male, n = 5,824).^72^ This was done by comparing fracture rates (not limited to fragility fracture) between Veterans with antipsychotic use and a control group of Veterans (not on antipsychotics) matched for several key comorbidities, including: heart failure, emphysema, depression, diabetes, end-stage renal disease, and schizophrenia. Smoking and alcohol use were not adjusted for in multivariable analysis, and these exposures were significantly more prevalent in Veterans on antipsychotic medications. Despite this, prevalence of fracture was similar between Veterans with (10.0%) and without (10.2%) long-term antipsychotic use in this study, and authors found no significant association with fracture.

Table 5 Assessment of Individual Risk Factors

Author, Year | Risk factors; Total n | Prevalence OR | Outcome metric | Effect size (95% CI) | ROB
Munigala, 2016^69^ | Chronic pancreatitis; Total n = 3079 | 153 fractures/3257 people with chronic pancreatitis | Fracture at all sites | adjusted OR 1.73% (1.46 to 2.05); p < 0.0001 | High risk
Munigala, 2016^69^ | Chronic pancreatitis; Total n = 3079 | 153 fractures/3257 people with chronic pancreatitis | Hip fracture | adjusted OR 2.69% (2.13 to 3.40); p < 0.0001 | High risk
Munigala, 2016^69^ | Chronic pancreatitis; Total n = 3079 | 153 fractures/3257 people with chronic pancreatitis | Vertebral fracture | adjusted OR 1.56% (1.06 to 2.31); p = 0.0257 | High risk
Munigala, 2016^69^ | Chronic pancreatitis; Total n = 3079 | 153 fractures/3257 people with chronic pancreatitis | Wrist fracture | adjusted OR 1.18% (0.90 to 1.55); p = 0.2382 | High risk
Munigala, 2016^69^ | Chronic pancreatitis (age 45–65); n = 2038 | 153 fractures/3257 people with chronic pancreatitis | Fracture at all sites | OR 2.41 (1.96 to 2.96); p < 0.0001 | High risk
Munigala, 2016^69^ | Chronic pancreatitis (age > 65); n = 525 | 153 fractures/3257 people with chronic pancreatitis | Fracture at all sites | OR 2.75 (1.99 to 3.80); p < 0.0001 | High risk
Hsieh, 2019^71^; VACS cohort | Osteomyelitis; n = 24451 | 6.5% fracture in men with osteomyelitis; 3.8% in men without osteomyelitis | All fracture (hip, upper arm, vertebra) | Adjusted OR 1.649 (1.154 to 2.356) | Unclear
Hsieh, 2019^71^; VACS cohort | Osteomyelitis; n = 24451 | 6.5% fracture in men with osteomyelitis; 3.8% in men without osteomyelitis | Hip fracture | Adjusted OR 1.762 (0.944 to 3.289) p 0.08 | Unclear
Hsieh, 2019^71^; VACS cohort | Osteomyelitis; n = 24451 | 6.5% fracture in men with osteomyelitis; 3.8% in men without osteomyelitis | Upper arm fracture | Adjusted OR 1.95 (1.016 to 3.744) p 0.04 | Unclear
Hsieh, 2019^71^; VACS cohort | Osteomyelitis; n = 24451 | 6.5% fracture in men with osteomyelitis; 3.8% in men without osteomyelitis | Vertebral fracture | Adjusted OR 2.428 (1.173 to 5.029), p 0.02 | Unclear
Hall, 2018^73^ | CKD stage 3; n = 339,278 | 12.4% without CKD had fractures over median 5.2 years follow up vs 15.7% of those with CKD | Fracture by ICD and CPT codes | Cox proportional adjusted HR 0.95 (0.91 to 0.99); Fine and Gray^a^ Adjusted subdistribution HR 1.07 (1.02 to 1.11) | Unclear
Hall, 2018^73^ | CKD stage 4; n = 15,167 | 12.4% without CKD had fractures over median 5.2 years follow up vs 15.7% of those with CKD | Fracture by ICD and CPT codes | Cox proportional adjusted HR 1.32 (1.16 to 1.49); Fine and Gray^a^ Adjusted subdistribution HR 1.07 (0.94 to 1.22) | Unclear
Hall, 2018^73^ | CKD stage 5; n = 2,014 | 12.4% without CKD had fractures over median 5.2 years follow up vs 15.7% of those with CKD | Fracture by ICD and CPT codes | Cox proportional adjusted HR 1.91 (1.45 to 2.50); Fine and Gray^a^ Adjusted subdistribution HR 1.31 (0.97 to 1.77) | Unclear
Shahani, 2019^79^; VACS cohort | VACS frailty index | 109 (56%) had osteoporosis or osteopenia out of 195 | DXA T-score or Z-score; Reference population NR | Odds of low BMD increasing 1.21 times for each 10-unit increase in VACS Index score [confidence interval (95% CI) 1.03–1.42; p = .02] | High risk
Womack, 2013^75^; VACS cohort | VACS frailty index; n = 40,115 | 588 first fragility fractures (210 hip, 111 vertebral, 267 upper arm) | Fragility Fracture; (composite of hip, vertebral and upper arm fractures, defined using ICD-9 codes) | HR for covariate-adjusted association between fragility fracture and VACS Index Score (for 10-unit increase in index): 1.15 (1.11 to 1.19) | Unclear
Hain, 2011^76^ | PTSD; 320 (only 61 had PTSD, 19.1%) | NR | Total hip T-score; Reference population NR | F (2,313) = 3.02, p < 0.05, partial h^2^; = 0.02 | High risk
Hain, 2011^76^ | PTSD; n = 320 (only 61 had PTSD, 19.1%) | NR | Total spine T-scores; Reference population NR | F (2,313) = 1.54, p < 0.22, partial h^2^; = 0.01 | High risk
Womack, 2011^77^; VACS cohort | HIV; n = 119,318 men, 33% of whom were HIV infected | 1615 first fractures (496 hip, 322 vertebral, and 797 upper arm fractures) | ICD9 based fragility fracture of hip, vertebrae, or upper arm | Adjusted HR (without BMI): 1.24 (1.11, to 1.39); Adjusted HR (including BMI and BMI squared): 1.10 (0.97 to 1.25) | Unclear
Akhter, 2009^78^ | Vitamin D 25-OHD > 15 ng/ml (Group I); n = 54 | Group I: 3.7% with osteoporosis; Group II: 3.5% with osteoporosis; Group I: 25.9% with osteopenia; Group II: 19% with osteopenia | BMD of spine | Correlation coefficient r = 0.13, p >0.05 | Unclear
Akhter, 2009^78^ | Vitamin D 25-OHD > 15 ng/ml (Group I); n = 54 | Group I: 3.7% with osteoporosis; Group II: 3.5% with osteoporosis; Group I: 25.9% with osteopenia; Group II: 19% with osteopenia | BMD of hip | Correlation coefficient, r = 0.18, p>0.05 | Unclear
Akhter, 2009^78^ | Vitamin D 25-OHD ≤ 15 ng/ml (Group II); n = 58 | Group I: 3.7% with osteoporosis; Group II: 3.5% with osteoporosis; Group I: 25.9% with osteopenia; Group II: 19% with osteopenia | BMD of spine | Correlation coefficient r = 0.26, p = 0.05 | Unclear
Akhter, 2009^78^ | Vitamin D 25-OHD ≤ 15 ng/ml (Group II); n = 58 | Group I: 3.7% with osteoporosis; Group II: 3.5% with osteoporosis; Group I: 25.9% with osteopenia; Group II: 19% with osteopenia | BMD of hip | Correlation coefficient: r = 0.27, p < 0.05 | Unclear
Sinnott, 2006^51^ | Weight based calculation (WBC); n = 128 | Osteopenia: 39%; Osteoporosis: 7% | T-score ≤ −2.5 at the hip; (T-scores were calculated using the manufacturer’s reference values [young Caucasian male database]) | AUC/ROC 0.75 (0.57 to 0.92) | At risk (QUADAS)
Sinnott, 2006^51^ | BMI; n = 128 | Osteopenia: 39%; Osteoporosis: 7% | T-score ≤ −2.5 at the hip; (T-scores were calculated using the manufacturer’s reference values [young Caucasian male database]) | AUC/ROC 0.67 (0.47 to 0.87) | At risk (QUADAS)
Papaleontiou, 2019^70^ | Thyroid cancer; n = 539 | n = 539, 6.2% male patients with thyroid cancer; n = 349, 4.0% male patients without thyroid cancer and not on LT4 | Osteoporosis by ICD-9 codes (733.0x) | OR 1.46 (1.26 to 1.68) | Unclear
Papaleontiou, 2019^70^ | Thyroid cancer; n = 212 | n = 212, 2.4% fractures in male patients with thyroid cancer; n = 241, 2.8% fractures in male patients without thyroid cancer | Fracture by ICD and CPT codes | OR 0.70 (0.58 to 0.85)
Khan, 2013^74^ | Smoking; n = 2708 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Low BMD (Combines osteopenia [T-score ≤ −1.5] and osteoporosis [T-score ≤ −2.5]) | OR 1.2 (1.1 to 1.4) | High risk
Khan, 2013^74^ | Hyperparathyroidism (primary/ secondary),; n = 414 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Low BMD (Combines osteopenia [T-score ≤ −1.5] and osteoporosis [T-score ≤ −2.5]) | OR 2.8 (2.2 to 3.5)
Khan, 2013^74^ | Hypogonadism; n = 1386 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Low BMD (Combines osteopenia [T-score ≤ −1.5] and osteoporosis [T-score ≤ −2.5]) | OR 2.3 (2.0 to 2.7)
Khan, 2013^74^ | Obesity; n = 10,718 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Low BMD (Combines osteopenia [T-score ≤ −1.5] and osteoporosis [T-score ≤ −2.5]) | OR 0.8 (0.7 to 0.9)
Khan, 2013^74^ | Alcoholism; n = 3644 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Low BMD (Combines osteopenia [T-score ≤ −1.5] and osteoporosis [T-score ≤ −2.5]) | OR 0.9 (0.8 to 1.0)
Khan, 2013^74^ | Malnutrition; n = 316 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Low BMD (Combines osteopenia [T-score ≤ −1.5] and osteoporosis [T-score ≤ −2.5]) | OR 2.0 (1.5, to 2.7)
Khan, 2013^74^ | Vitamin D deficiency; n = 2053 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Low BMD (Combines osteopenia [T-score ≤ −1.5] and osteoporosis [T-score ≤ −2.5]) | OR 2.9 (2.6 to 3.3)
Khan, 2013^74^ | Prednisone cumulative dose decile >11136 (mg); n = 1076 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Low BMD (Combines osteopenia [T-score ≤ −1.5] and osteoporosis [T-score ≤ −2.5]) | OR 8.9 (7.8 to 10.2)
Khan, 2013^74^ | Smoking; n = 2708 (patients with ulcerative colitis) | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Fragility fracture | OR 1.6 (1.2 to 2.0)
Khan, 2013^74^ | Hyperparathyroidism (primary/ secondary),; n = 414 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Fragility fracture | OR 1.0 (0.6 to 1.7)
Khan, 2013^74^ | Hypogonadism; n = 1386 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Fragility fracture | OR 1.3 (0.9 to 1.8)
Khan, 2013^74^ | Obesity; n = 10718 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Fragility fracture | OR 1.2 (1.0 to 1.5)
Khan, 2013^74^ | Alcoholism; n = 3644 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Fragility fracture | OR 1.8 (1.4 to 2.3)
Khan, 2013^74^ | Malnutrition; n = 316 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Fragility fracture | OR 2.0 (1.2 to 3.4)
Khan, 2013^74^ | Vitamin D deficiency; n = 2053 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Fragility fracture | OR 1.9 (1.5 to 2.4)
Khan, 2013^74^ | Prednisone cumulative dose decile >11136 (mg); n = 1076 | 2239/34665 with osteoporosis, 6.5% of total cohort; 1506/34665 osteopenic, 4.3% of total cohort; 588/34665 fragility fracture, 1.7% of total cohort. | Fragility fracture | OR 1.8 (1.3 to 2.5)
Weaver 2019^72^ | Antipsychotic use; n = 5824 | 578 men with antipsychotic use with fractures/5824 men with antipsychotic use, 578 men without antipsychotic use with fractures/5667 men without antipsychotic use (approx. 10% in both groups) | Fracture | NR | High risk

a Fine and Gray odds ratio adjusted for death as competing event.

## QUALITY OF EVIDENCE FOR KEY QUESTION 2

### Studies Examining Osteoporosis and/or Fracture Risk Prediction Tools

Using the QUADAS tool, there were 2 low risk of bias^28,48^ and 6 “at risk of bias” studies across all studies that examined risk assessment tools for osteoporosis and/or fracture among Veterans (Figures 12, 13).^26,51,53,54,56,67^ Patterns that led to judgments of “at risk of bias” included: 1) selection of patients (5 studies), 2) interpretation of the index test (5 studies), 3) interpretation of reference standard (1 study), and 4) patient flow (1 study).

### Studies Examining Individual Risk Factors for Osteoporosis and Fracture

All studies examining individual risk factors for low BMD or fracture were unclear or high risk of bias (Figures 14, 15, 16).^51,69–79^ As a result, the quality of evidence for individual risk factors among male Veterans is very low, and additional work is needed fill these knowledge gaps.

Figure 12 Risk of Bias for Included KQ 2 Studies Evaluating Combined Risk Factors for Osteoporosis and/or Fracture in Male Veterans

Figure 13 Risk of Bias Across KQ 2 Studies Evaluating Combined Risk Factors for Osteoporosis and/or Fracture in Male Veterans

Figure 14 Risk of Bias for Included Studies Evaluating Individual Risk Factors for Osteoporosis and/or Fracture in Male Veterans

Figure 15 Risk of Bias for Included Case-Control Study Evaluating Individual Risk Factors for Osteoporosis and/or Fracture in Male Veterans

Figure 16 Risk of Bias Across Included KQ 2 Studies Evaluating Individual Risk Factors for Osteoporosis and/or Fracture in Male Veterans

## KEY QUESTION 3 What system-level interventions improve uptake of osteoporosis screening among people not identified by a history of low-trauma fracture?

### Characteristics of Included Studies

In total, 20 studies were included examining system-level interventions to improve the uptake of osteoporosis screening among people without a history of low-trauma fracture. Because some studies had more than 1 active intervention arm, a total of 24 intervention arms are described across the 20 studies. Interventions for these studies fell into 8 different categories: 1) provider education (5 studies^92–96^), 2) provider and patient education (3 studies^93,97,98^), 3) provider-focused reminders (4 studies^99–102^), 4) clinical decision support tools (1 study^103^), 5) patient navigation (2 studies^97,104^), 6) patient risk assessment (3 studies^105–107^), 7) patient self-referral (4 studies^108–111^), and 8) patient-focused reminders (1 study^102^). Table 2 shows the evidence profile for the studies.

For KQ 3, we present the detailed results ordered by provider- and patient-focused intervention approaches. When studies assessed the impact of multiple approaches, we synthesized results based on the major emphasis of the intervention approach (eg, robust provider education + generic patient education categorized as “provider education”). Details on study characteristics are in Appendix C and a summary of study results by intervention approach are in Tables 6-13.

### KeyKey Points

- Overall, a majority of the identified systems-level interventions in the literature excluded male patients and the most common category of interventions targeted providers (12 studies).
- Provider-focused approaches have mixed effectiveness in improving uptake of osteoporosis screening. Combining provider interventions with targeted patient education improves impact of the intervention but gains are modest significant.
  ○ Provider education-only interventions (eg, CME) demonstrated no increases uptake of osteoporosis screening (4 studies).
  ○ Provider-focused reminder systems (4 studies) improve uptake of osteoporosis screening via DXA. The impact is greater if provider prompts are coupled with patient education approaches.
  ○ Clinical decision support tools that combine tailored risk-based education for patients and tailored provider recommendations at the point of clinic visit show promise but have only been evaluated in 1 study.
- Ten studies evaluated the effect of patient-focused approaches on uptake of osteoporosis screening. Overall, patient-focused approaches of patient navigation (2 studies), patient risk assessment (2 studies), patient reminders (1 study), and self-referral systems (4 studies) improve osteoporosis screening via DXA.
  ○ Coupling patient approaches with provider-focused approaches only marginally increased effectiveness when compared to usual care. Systems redesign approaches that allow patients to self-refer for screening may be more effective if using fixed appointments compared to open invitations to self-refer without a fixed appointment.

### [image]Detailed Findings

### Provider-focused Intervention Approaches

Twelve studies (8 randomized trials,^92–95,97,98,100,102^ 3 nonrandomized trials,^96,99,101^ 1 interrupted time series^103^) evaluated the effect of provider-focused approaches on uptake of osteoporosis screening. All studies compared uptake of BMD (ie, DXA screening rates) between different provider-focused approaches compared to usual care. Next, we synthesize findings by typology of intervention approach. When meta-analysis was not able to be performed, we computed odds ratios from data reported and display these in the forest plots to add comparability between studies when feasible. We also include estimates provided in the included study.

#### Provider Education

Five studies (4 randomized trials^92–95^ and 1 nonrandomized trial^96^) focused on provider education as the only intervention approach to improve uptake of BMD testing for osteoporosis screening. Approaches ranged in intensity and dose from a 1-hour case-based session^92^ and testing to provider education coupled with a population health management approach^95^ (ie, list of patients due for BMD testing). Two studies targeted patients age-eligible for osteoporosis screening but 1 only focused on women.^92^ Two studies focused on special populations of patients: 1 focused on patients with a history of long-term glucocorticoid use^94^ and another on patients with rheumatoid arthritis.^95^ Four studies provided sufficient information for meta-analysis and all compared some form of provider education to usual care.^92–95^

Overall, these 4 randomized studies showed no benefit of provider education on uptake of osteoporosis screening (OR 0.98; 95% CI 0.39 to 2.50), although there was significant heterogeneity in intervention effects across studies (Q 8.8; p=0.032; I^2^ 66.0%) (Figure 15). We conducted exploratory subgroup analysis to assess the impact of enhanced provider education (ie, education + audit and feedback to providers, education + list of eligible patients) and special populations used in 2 studies.^94,95^ Subgroup analysis by type of provider education and by patient population did little to explain the heterogeneity across studies.

All studies in the meta-analysis were judged at unclear or high ROB. One additional high ROB study also assessed the impact of provider education but was not able to be included in the analysis.^96^ This study assessed the impact of didactic lectures on osteoporosis management, compared to no education among primary care physicians, and found no evidence of impact on ordering BMD for eligible patients (33.6% vs 34%).

Table 6 Provider Education

Study | Intervention | Results
Dolan, 2015^92^ | Provider education of 1-hour brief case-based session and assessment by 25 multiple choice questions | Provider Education: 216 / 227; Usual Care: 206 / 231; % difference 0.06% (95% CI 0.01 to 0.11); Calculated OR^a^ 2.38 (95% CI 1.14 to 4.97)
Solomon, 2007^93^ | Provider education with academic detailing | Provider Education: 183 / 3,274; Usual Care: 224 / 3,268; Calculated OR^a^ 0.80 (95% CI 0.66 to 0.98)
Curtis, 2007^94^ | Provider education with audit and feedback; Special population: long-term glucocorticoid use | Provider Education: 19 / 472; Usual Care: 21 / 477; Risk difference: −2 (95% CI −8 to 4); Calculated OR^a^ 0.91 (95% CI 0.48 to 1.72)
Solomon, 2003^95^ | Provider education (mailing of recommendations), academic detailing (dinner meeting), and population health management (curated list of RA patients who were due for BMD testing) vs UC (population: RA) | Provider education and panel management: NR; Usual Care: NR; OR 0.50 (95% CI 0.2 to 1.5)
Pazirandeh, 2002^96^ | Provider education (CME) and patient education was conducted for all patients in the study | Provider education (CME): 33.6%; Usual Care: 34%; OR not reported or calculated

a OR calculated by investigators to create a standard metric across studies.

Figure 17 Impact of Provider Education on Update of Osteoporosis Screening

### Provider and Patient Education

Three studies (2 randomized controlled trials and 1 cluster-randomized control trial [CRT]),^93,97,98^ all with unclear ROB, evaluated the combined effect of provider and patient education on screening rates for osteoporosis to standard care. One of the studies included only men on androgen deprivation therapy,^97^ and the other 2 studies included mostly women (92%–97%). Due to differences in study design, interventions assessed, and outcome reporting, a meta-analysis was not performed. Figure 7 displays the estimates for each study.

The first study assessed the impact of 1-on-1 education by a physician educator coupled with written CME education and curated list of patients at risk of osteoporosis (n = 1973).^98^ Patients received education consisting of an automated telephone call employing interactive voice response (IVR) to provide targeted education and invitation to screen, with the option to transfer the call to schedule BMD testing. At 10 months’ follow-up, patients in the intervention arm were more likely to attend BMD screening compared to patients receiving usual care (RR=1.48; 95% CI 1.08 to 2.04). The next study included only males on androgen deprivation therapy (n = 119) and compared usual care with a pamphlet education for patients and printed material to the family physician.^97^ At 10 months’ follow-up, men exposed to the intervention were significantly more likely to seek a BMD test (OR 2.7; 95% CI 1.19 to 6.15). The last study included 13,455 patients and compared usual care to 3 interventions: generic written patient education, brief provider education through academic detailing by a trained physician educator, and a combined approach of these 2 interventions.^93^ Compared to usual care, the combined intervention found no significant impact on uptake of BMD testing at 16 months follow-up (6.9 vs 10.9, p value not reported). Overall, the 2 studies that coupled provider education with targeted patient education demonstrated a statistically significant, modest impact of the combined intervention.^97,98^ The study that combined provider education with generic written patient education showed no statistically significant increase in BMD.^93^

Table 7 Provider and Patient Education

Study | Intervention | Results
Solomon, 2007^98^ | Patient education of IVR call with education and the option to transfer to scheduling for BMD testing + provider education of individual session with physician educator pharmacist, written education on osteoporosis diagnosis, management and treatment for CME, and curated list of patients in their practice at risk for osteoporosis | Provider Education and patient education: 126 / 997; Usual Care: 86 / 976; Risk Ratio: 1.48 (95% CI 1.08 to 2.04); Calculated OR^a^ 1.50 (95% CI 1.12 to 2.00)
Alibhai, 2018^97^ | Patient received of 10-page educational pamphlet + mailed education material to family physician; Special population: men with history of androgen deprivation therapy | Patient Education + Provider Education: 23/40; Usual Care: 13/36; OR 2.7 (95% CI 1.19 to 6.15); Calculated OR^a^ 2.39 (95% CI 0.95 to 6.04)
Solomon, 2007^93^ | Patient education (not tailored) + in-person provider education by a physician educator informed by academic detailing principles | Provider Education and patient education: 223 / 3,339; Usual Care: 224 / 3,268; Calculated OR^a^ 0.97 (95% CI 0.80 to 1.18)

a OR calculated by investigators to create a standard metric across studies.

Figure 18 Impact of Provider Education plus Patient Education on Uptake of Osteoporosis Screening

### Provider-focused Reminders

Four studies (2 nonrandomized trials,^99,101^ 2 CRTs^100,102^) evaluated the impact of provider-focused reminders on uptake of BMD testing. Three of these studies were of unclear ROB^100–102^ and 1 had high ROB.^99^ All but 1 study used EMR-based provider reminders.^100^ Two studies assessed the impact of additional intervention approaches of patient education^100^ or panel management to provider reminder systems.^101^ Only 1 study included men; all other studies focused on women age-eligible for BMD screening.^99^ Studies were too varied to conduct meta-analysis. Figure 8 displays point estimates for each of the arms in 3 studies; we were not able to convert 1 study to a common metric for visual display.^102^

The first CRT was a large (n = 10354) assessment of a generic mailed patient reminder alone or paired with physician EHR-based prompts for osteoporosis screening conducted in 15 primary care clinics.^102^ Patient reminders alone (24.1%), or in combination with provider prompts (28.9%), significantly increased BMD testing compared to usual care (10.8%; p < 0.001). The next CRT conducted an assessment of chart reminders in the form of paper sticky notes alone or in combination with mailed generic patient education in 5 primary care clinics (n = 195).^100^ Chart reminders in combination with patient education (45.2%; OR 5.47, p = 0.029) increased BMD testing among age-eligible women compared to usual care (9.7%). Yet, while chart reminders alone increased screening, the impact was not statistically significant (OR 2.37, p = 0.156).

The first nonrandomized study assessed the impact of EHR-based reminders for 4 preventive practice behaviors (ie, osteoporosis screening via BMD, influenza and pneumococcal vaccinations, and health care proxy designation) alone or in combination with a panel manager compared to usual care (n = 4660).^101^ The panel manager approach was an off-site administrative assistant who reviewed patient panels for patients due for any of the 4 behaviors. The panel manager then emailed the provider a list of patients due and asked permission to contact. If permission was granted, the panel manager called the patient and facilitated completion of the needed services. Compared to usual care, both arms increased BMD testing, but only the provider reminder arm combined with panel management was statistically significant (OR 2.31; 95% CI 1.55 to 3.43). The next nonrandomized study (high ROB) also assessed the impact of EMR-based reminder on a cluster of 3 practice behaviors but included actionable links to computerized orders (n = 3849).^99^ While provider reminders increased screening, the impact was not significant (OR 1.29; 95% CI 0.82 to 2.02). Overall, the 4 included studies suggest that provider reminders improve uptake of osteoporosis screening via BMD. The impact is greater if provider prompts are coupled with patient education approaches.

Table 8 Provider-focused Reminders

Study | Intervention | Results
El-Kareh, 2011^99^ | EMR-based reminders with actionable link to computerized order for 3 practice behaviors, including osteoporosis screening | System reminder - provider: 114 / 1,865; Usual Care: 115 / 1,984; OR 1.29 (95% CI 0.82 to 2.02)
Levy, 2009^100^ | Provider: Printed sticky practices could place on patient charts; Patient: Mailed generic patient education | Chart reminder + mailed patient education vs Usual Care: OR 5.47 (p = .029); Calculated^a^ (95% CI 1.92 to 15.57); Chart reminder vs Usual Care: OR 2.37 (p = .156); Calculated^a^ (95% CI 1.18 to 4.77)
Loo, 2011^101^ | EMR reminders for 4 preventive practice behaviors, including osteoporosis screening; EMR + panel manager arm off-site panel manager reviewed, geriatrics patient list for patients due for any of 4 behaviors, emailed provider for permission to contact patient and called patient to facilitate completion of needed health services.; If unable to contact patient, a letter with the same content that would have been provided by telephone was sent | Provider reminder vs Usual Care:; OR 1.43 (95% CI 0.94 to 2.17); Provider reminder + panel management vs usual care; OR 2.31 (95% CI 1.55 to 3.43)
Lafata, 2007^102^ | EHR-based provider reminder + generic mailed patient reminder | All patients 65+:; Usual Care (10.8%) vs Patient mailed reminder and physician prompt (28.9%), (p<0.001).; Age 65: Usual Care 17.0 (13.8 to 20.9), Patient mailed reminder and physician prompt: 30.3 (27.8 to 32.9); Age 75: Usual Care 10.1 (8.0 to 12.6) Patient mailed reminder and physician prompt: 27.0 (24.7 to 29.4); Age 85: Usual Care: 5.8 (4.5 to 7.3) Patient mailed reminder and physician prompt: 23.9 (21.8 to 26.2); BMD Testing Age × Patient mailed reminder and physician prompt: Beta = 0.04 (SE = 0.01), p < 0.01; OR not reported and unable to be calculated

a OR calculated by investigators to create a standard metric across studies.

Figure 19 Impact of Provider-focused Reminders on Uptake of Osteoporosis Screening

### Clinical Decision Support Tools

One high ROB study assessed the impact of a clinical decision support tool on age-eligible men (aged 65+) and women (aged 50+) using an interrupted time-series design.^103^ The study was conducted in 3 family practices encompassing 5 physicians and 2840 eligible patients. The intervention was completed at the time of the clinical visit with 3 components: risk assessment questionnaire for patients completed on a tablet, paper-based best practices prompt for physicians based on responses from the patient, and customized osteoporosis educational sheet given to patients at the end of the physician visit summarizing individualized risk and suggestions for managing those risks. Results showed an increase from baseline in initiation of screening (3.4%; p < 0.001).

Table 9 Clinical Decision Support Tool

Study | Intervention | Results
Kastner, 2014^103^ | Risk assessment tool given to patient in waiting room. The system gives a individualized, person specific printout for provider with treatment recommendations. The system also gives the patient a specific educational printout at the end of the visit. | Clinical decision support tool; Mean 6.15 (SD 2.24); Usual Care; Mean 2.79 (SD 1.27); % change: 3.4% (95% CI 2.03 to 4.68); OR not reported or calculated

### [image]Patient-focused Intervention Approaches

Ten studies (8 randomized trials,^97,102,105–109,111^ 1 controlled before and after study,^110^ 1 interrupted time-series study^104^) evaluated the effect of patient-focused approaches on uptake of osteoporosis screening. All studies compared uptake of BMD (ie, DXA screening rates) between different patient-focused approaches or compared to usual care. Below we synthesize findings by typology of intervention approach. When meta-analysis was not able to be performed, we computed odds ratios from data reported and display these in the forest plots to add comparability between studies when feasible. We also include the estimates provided in the study.

#### Patient Navigation

Two studies (1 RCT,^97^ 1 interrupted time-series study^104^) assessed the impact of patient navigation on uptake of osteoporosis screening. Both studies were judged to be unclear ROB. The first study was a single-center RCT with men on androgen deprivation therapy (n = 119) and compared usual care with a pamphlet education for patients plus individual patient navigation by a bone health care coordinator who followed up at least twice over 3 months to facilitate BMD ordering.^97^ At 10 months’ follow-up, men exposed to the intervention were significantly more likely to seek a BMD test (OR 2.7; 95% CI 1.19 to 6.15). The interrupted time-series study was conducted in women only (pre-intervention n = 1782; post-intervention n = 1981) and assessed the impact intervention consisting of mailed and telephone contacts with an outreach coordinator authorized to schedule a screening appointment without a provider visit first compared to usual care.^104^ Over 13 months of the intervention period, the percent increase in the population screened that was attributable to the outreach coordinator was 13% (p < 0.001). Overall, both studies suggest a positive impact on patient navigation strategies on uptake of osteoporosis screening.

Table 10 Patient Navigation

Study | Intervention | Results
Alibhai, 2018^97^ | Patient received 10-page educational pamphlet + 1-on-1 session with a bone health care coordinator who followed up at least twice over 3 months to facilitate BMD ordering | Patient education + bone health care coordinator navigation : 23/40; Usual Care: 13/36; OR: 2.7 (95% CI 1.19, 6.15)
Denberg, 2019^104^ | An invitation letter was mailed to each patient and included the name of the patient’s PCP, summarized the USPSTF recommendations and rationale for DXA, and encouraged the patient to contact the call center to arrange an examination. If the patient did not respond within 2 weeks, the outreach coordinator made up to 3 calls to the patient’s home at different times of the day over a period of 8 weeks, leaving a voice message on the first attempt. | Patient education + navigation vs usual care: p < .001; OR: not reported or calculated

#### Patient Risk Assessment

Three studies (1 CRT, 2 individual-level RCTs) assessed the impact of patient risk assessment (eg, calculating FRAX).^105–107^ Two of these studies were judged unclear ROB,^105,107^ and 1 low ROB^106^; only 1 study included men.^106^ Due to differences in study design, interventions assessed, and outcome reporting, we did not perform meta-analysis.

The first study was a low ROB RCT that assessed the impact of a community pharmacist screening program on osteoporosis testing via BMD and treatment among 262 people age-eligible for screening or with at least 1 major risk factor for fracture.^106^ The intervention consisted of generic printed patient education, quantitative heel ultrasound, and risk assessment feedback via the community pharmacist compared to a usual care. At 4 months’ follow-up, community dwelling participants exposed to the intervention were significantly more likely to undergo BMD testing compared to controls (RR = 2.20; 95% CI 1.2 to 4.1). The next study was an unclear ROB RCT that sent 34,229 randomized women in Denmark to an intervention or control group.^107^ All women in the study were mailed a FRAX and asked to mail it back. Women in the intervention arm were offered a DXA scan if their 10-year probability of MOF was 15% or greater. Women in the control group received no further communication. Approximately 80% returned the questionnaire; 10-year risk of osteoporotic fracture was able to be calculated for 61% of all women in the study. The intervention had no overall impact of MOF after a mean follow-up time of 5 years (p=0.682). The last study was an unclear ROB RCT among 4685 women aged 50 to 64 with an elevated risk of developing osteoporosis.^105^ Women were randomized to usual care or 1 brief telephonic IVR call which calculated a fracture risk-score based on women’s responses, history of BMD testing, and intentions to discuss osteoporosis with their physician. The call ended with a recommendation to discuss BMD testing with their physician. Women randomized to receive IVR intervention were significantly more likely to obtain BMD within 12 months compared to usual care (25.6% intervention vs 18.6% in usual care; p < 0.001). Overall, patient risk assessment showed promise at increasing BMD screening when coupled with individualized feedback on risk in 2 studies.^106^ Only 1 study assessed risk of fracture and found no impact of administering the FRAX coupled with invitation to screen and no feedback on risk.^107^

Table 11 Patient Risk Assessment

Study | Intervention | Results
Heyworth, 2014^105^ | Patient IVR was a call lasting 4-5 minutes in which the automated response recognized the patient and confirmed identification. The call ascertained the patients’ fracture risk score and the following information: history of BMD testing, plans to follow up with their physician to discuss osteoporosis. | Patient Risk Assessment and feedback: 385 / 1,565; Usual Care: 290 / 1,558; Percent difference: 6% (p < 0.001)
Yuksel, 2010^106^ | Risk assessment with community pharmacist via quantitative heel ultrasound, plus generic patient education | Patient Risk Assessment and feedback: 28 / 129; Usual Care: 13 / 133; Risk Ratio: 2.2 (95% CI 1.2, 4.1)
Rubin, 2018^107^ | All participants were mailed a questionnaire. Questionnaires with fewer than 3 missing items were used to calculate a FRAX score. Intervention arm participants received an offer for a DXA if they had a 10-year probability of fracture of 15% or more. Results of DXA were shared with patient and GP | Patient Risk Assessment and feedback: 1,697 / 17,072; Usual Care: 1,719/17,157; Sub-hazard ratio of MOF: 0.986 (95% CI 0.922; 1.055); Patient Risk Assessment and feedback: 534 / 17,072; Usual Care: 532 /17,157; Sub-hazard ratio hip fracture: 1.002 (95% CI 0.889; 1.130)

#### Patient Self-referral

Four studies (2 RCTs, 1 CRT, 1 controlled before-after study) evaluated the effect of patients’ ability to self-refer for osteoporosis screening.^108–111^ All studies were judged unclear ROB. No studies included men. In total, 19,740 women were included in those trials, and screening rates from 90 days to 5 months were evaluated. All interventions across the 4 studies involved a mailed reminder. Three of the studies’ interventions were mailed reminders to call and schedule an osteoporosis screening compared to a no-contact control.^108–110^ One study compared 3 different types of self-referral invitations (ie, fixed appointment that required telephone confirmation of intent to attend screening, fixed appointment with option to change time but no need to call to confirm, open invitation with no preassigned appointment slot)^111^ and 1 study compared mailed self-referral alone or with additional patient education in the form of a DVD by trial site (ie, Northwestern, Georgia).^109^ Due to differences in study design and outcome reporting, meta-analysis could not be performed. Figure 18 displays the point estimates for each of the 9 comparisons across the 4 studies.

In the 3 interventions with mailed invitations to self-referral only compared to usual care, self-referral resulted in a statistically significant increase in osteoporosis screening (OR range: 2.70 to 4.87).^108–110^ In the study assessing additional patient education via a mailed DVD, self-referral significantly improved osteoporosis screening over no-contact control at each of the 2 trial sites, but the increases were similar to the condition receiving self-referral invitation alone.^109^ In the study that assessed 3 different types of self-referral procedures,^111^ fixed appointment invitations (75% screened) and confirmable invitations (69% screened) significantly increased osteoporosis screening over open invitations to call and schedule a screening (54%; p < 0.0001). Yet fixed reminders did not result in statistically significant increases in osteoporosis screening over confirmable reminders (p = 0.083). Overall, all studies demonstrated a statistically significant impact of self-referral approaches to improving osteoporosis screening.

Table 12 Patient Self-referral

Study | Intervention | Results
Warriner, 2014^109^ | Intervention 1: Selected eligible patients received a mailed invitation for self-referral for DXA scan. All physicians were educated and provided information regarding osteoporosis.; Intervention 2: Patients received a mailed invitation for self-referral for DXA scan and patient education via DVD. All physicians were educated and provided information regarding osteoporosis. | Kaiser Permanente Northwest self-referral vs Usual Care: OR 4.9 (95% CI 3.3, 7.1); Kaiser Permanente Northwest self-referral with patient educational materials vs Usual Care: OR 4.8 (95% CI 3.3, 6.9); Kaiser Permanente Georgia self-referral vs Usual Care: OR 2.7 (95% CI 1.5, 4.8); Kaiser Permanente Georgia self-seferral with educational materials vs Usual Care: OR 2.2 (95% CI 1.1, 4.4)
Warriner, 2012^108^ | Patients in this group were sent a letter and brochure detailing the importance of osteoporosis screening and offering guidance on how to self-schedule a DXA scan | Patient self-referral: 17.3%; Usual Care: 5.2%; OR: 2.9 (95% CI 1.7, 4.8); Calculated OR^a^: 3.82 (3.08, 4.74)
Ayoub, 2009^110^ | Patient self-referral with 1 follow-up call | Patient self-referral: 231/583; Usual Care: 104/789; Calculated OR^a^: 4.32 (3.32, 5.63)
Garton, 1992^111^ | Women were randomized to 3 types of mailed reminders:; Intervention 1: confirmable BMD appointment; Intervention 2: fixed BMD appointment; Intervention 3: open invitation to call and schedule a BMD screening but no set appointment | Patient self-referral (Fixed appt) vs open appointment:; Risk difference 12 (95% CI 14, 27); Calculated OR^a^: 2.50 (95% CI 1.85, 3.37); Patient self-referral (Confirmable appt) vs open appointment:; Risk difference 15 (95% CI 8, 22); Calculated OR^a^: 1.90 (95% CI 1.42, 2.54); Patient self-referral (Fixed appt) vs Patient self-referral (Confirmable appt):; Risk difference 6 (95% CI −1, 12); Calculated OR^a^: 1.31 (95% CI 0.96, 1.79)

a OR calculated by investigators to create a standard metric across studies.

Figure 20 Patient Self-referral on Uptake of Osteoporosis Screening

^a^ Kaiser Permanente Northwest Self-referral vs Usual Care

^b^ Kaiser Permanente Georgia Self-referral vs Usual Care

^c^ Kaiser Permanente Northwest Self-referral with Patient Educational Materials vs Usual Care

^d^ Kaiser Permanente Georgia Self-referral with Educational Materials vs Usual Care

#### Patient-focused Reminders

One unclear ROB CRT conducted in 15 primary care clinics (n = 10,354) assessed an intervention consisting of 2 mailed patient reminders timed to occur with the primary care visit and 1 month after the primary care visit alone, or paired with physician EHR-based prompts for osteoporosis screening.^102^ This study focused on women only. Patient reminders alone (24.1%), or in combination with provider prompts (28.9%), significantly increased BMD testing compared to usual care (10.8%; p < 0.001).

Table 13 Patient Reminders

Study | Intervention | Results
Lafata, 2007^102^ | Two generic mailed patient reminders sent to women with a recent visit to their primary care physician. | All patients 65+:; Patient mailed reminder: 24.1% (unadjusted); Usual Care: 10.8% (unadjusted); Results by age brackets:; Age 65:; Usual Care: 17.0% (13.8, 20.9); Patient Mailed Reminder: 23.2% (20.6, 25.9); Age 75:; Usual Care: 10.1% (8.0, 12.6); Patient Mailed Reminder: 18.7% (16.5,21.0); Age 85:; Usual Care: 5.8% (4.5, 7.3); Patient Mailed Reminder: 14.8% (13.1, 16.8); BMD Testing Age × Mailed Reminder: Beta = .03 (SE = .01), p = .01.; OR: not reported or calculated

## QUALITY OF EVIDENCE FOR KEY QUESTION 3

The ROB for patient-reported outcomes was judged low for 4 studies,^100,104,106,110^ unclear for 1 study,^97^ and high for 1 study.^96^ For objectively reported outcomes, the ROB was judged low for 3 study^104,106,110^ and unclear for 13 studies.^93–95,98,100–103,105,107–110^

Patterns that led to judgments of higher ROB included: 1) selection bias related to random sequence generation (n = 9), 2) differences in baseline measurement for study conditions (n = 11), and 3) outcome assessments that did not clearly blind to intervention assignment (n = 9). In addition to the lack of randomization for the 5 nonrandomized studies, (3 nonrandomized trials, 1 controlled before and after, 2 interrupted time-series studies), baseline provider contamination and incomplete outcome data led to a judgement of high ROB. The ROB ratings and assessments for each study are shown in Figures 19, 20, 21, and 22.

Figure 21 Risk of Bias Ratings for the Included Studies

Figure 22 Risk of Bias Assessment Across Included Studies

Figure 23 Risk of Bias Ratings for the Interrupted Time-Series Studies

Figure 24 Risk of Bias Assessment Across the Interrupted Time-Series Studies