# METHODS

We followed a standard protocol for this review developed in collaboration with operational partners and a technical expert panel. The PROSPERO registration number is CRD42020150830. The protocol was developed prior to the conduct of the review, and there were no significant deviations after registration. Each step was pilot-tested to train and calibrate study investigators. We adhered to the Preferred Reporting Items for Systematic Reviews and Meta Analyses (PRISMA) guidelines.^12^

## TOPIC DEVELOPMENT

This systematic review was requested by the Office of Specialty Care and the Osteoporosis Field Advisory Committee. The review will be used to identify the current evidence base and its quality to (1) support screening for osteoporosis and increased fracture risk in men, specifically in Veterans, and (2) identify interventions to improve the uptake of screening. Prior systematic reviews on this topic were inadequate for the needs of stakeholders because they did not include recent important studies and did not adequately consider components such as screening by risk factors or fracture risk—which are increased in Veterans—and system-based interventions to improve screening uptake.

## SEARCH STRATEGY

In collaboration with an expert reference librarian, we conducted a primary literature search from inception to June 28, 2019, for KQ 1 and KQ 2, and to July 22, 2019, for KQ 3, of MEDLINE^®^ (via PubMed^®^), Embase (via Elsevier), and CINAHL (via EBSCO). We subsequently updated the search for KQ 1, KQ 2, and KQ 3 in MEDLINE^®^ on February 23, 2021. We used a combination of database-specific subject headings and selected free-text terms (eg, osteoporosis, fracture assessment) to search titles and abstracts (Appendix A). We also conducted hand-searches of the references from select high-quality systematic reviews and exemplar studies identified during the topic development process and as identified by our stakeholders.

Our search strategy was informed by the Cochrane Effective Practice and Organization of Care (EPOC) Group.^13^ EPOC criteria were developed to capture both randomized and nonrandomized study designs. All citations were imported into 2 electronic databases (for referencing, EndNote^®^, Clarivate Analytics, Philadelphia, PA; for data abstraction, DistillerSR; Evidence Partners Inc., Manotick, ON, Canada).

## STUDY SELECTION

Key eligibility criteria for study inclusion in KQ 1 and KQ 2 meta-analyses were (1) study design: cohort, case-control, or cross-sectional; (2) study purpose: evaluation of clinical risk assessment tools (eg, FRAX^®^, Garvan, QFracture^®^, or Osteoporosis Self-assessment Tool [OST]); (3) study population: not identified by a prior low-trauma fracture; and (4) outcomes: osteoporosis, osteopenia (ie, BMD T-score between −1.0 and 2.5) with an additional risk factor, or fracture. KQ 2 additionally included studies that examined the association between osteoporosis or major osteoporotic fracture (MOF) and potential independent risk factors among male Veterans only. Studies could qualify for both KQ 1 and KQ 2, and we have highlighted these across both KQ 1 and KQ 2 Results sections.

Importantly, we did not include studies that intentionally recruited men because of a history of low-trauma fracture (eg, patients attending a clinic because of a fracture). While this group of men is clinically important to target for screening and treatment, populations recruited in this way may not be representative of the larger target population of men at risk and artificially inflate the fracture rate in the study population. However, studies with participants that happened to have a history of low-trauma fractures were still included. Eligible studies defined osteoporosis and osteopenia based on BMD T-scores (ie, BMD T-score ≤ −2.5 and BMD T-score between −1.0 and − 2.5 respectively). The International Society for Clinical Densitometry guidelines recommends using a standard Caucasian female reference for men of all ethnic groups.^14^. The reference groups used to calculate T-scores varied widely and this did not affect study eligibility. The definition of osteoporosis for this review does NOT include clinical osteoporosis diagnosis by prior fracture.

Eligibility criteria for KQ 3 included randomized trials, nonrandomized trials, controlled before-after studies, and interrupted time-series studies evaluating system-level interventions for increasing screening for osteoporosis among men or women not identified because of prior fracture.

We used the artificial intelligence (AI) technology developed as part of the DistillerSR software, called DistillerAI, to assist with screening abstracts.^15^ Using prespecified inclusion/exclusion criteria (Table 1), the titles and abstracts of a subset of articles (approximately n = 200) identified through our primary search were classified independently by 2 senior investigators (JMG, NS) for relevance to the KQs. After resolving disagreements between the investigators via consensus or by obtaining a third reviewer’s opinion, this set of included and excluded articles was used to train the Distiller AI program.

We used Distiller AI to screen the remaining titles and abstracts and assigned a prediction score of relevance to the study questions. All citations classified with a prediction score ≤ 0.5 underwent screening by a single investigator. Potentially relevant studies included by the investigator or with an AI prediction score > 0.5 underwent full-text screening. The sensitivity of machine-assisted screening was comparable to a single-reviewer screening (78% sensitivity for machine-assisted screening and single-reviewer screening). The specificity of machine-assisted screening was 95% with a 95% CI (0.92-0.97).^16^

At the full-text screening stage, 2 independent investigators agreed on a final inclusion/exclusion decision. Disagreements on eligibility were resolved by consensus or by obtaining a third reviewer’s opinion when consensus was not reached.^16^

Table 1 Study Eligibility Criteria

Study Characteristic | Include | Exclude
Population | KQ 1: Adult males; KQ 2: Adult male Veterans; KQ 1, KQ 2: Studies with mixed populations of men and women were included if they conducted a subgroup analysis of men only; for studies that analyzed both men and women together, a first-order approach was taken at full-text review.; KQ 3: Health care providers, adult patients, health system administrators and/or staff.; KQ 3: For studies that recruit populations with and without facture histories, 80% of recruited study population should have no prior identified low-trauma fracture. | KQ 1, KQ 2:; - Children; - Other metabolic bone diseases (eg, osteogenesis imperfecta, osteomalacia/ rickets, renal osteodystrophy, primary hyperparathyroidism, Paget’s, osteopetrosis); - History of low-trauma fractures^a^; KQ 3: Children
Intervention | KQ 1: Clinical risk assessment or fracture risk prediction tools such as Fracture Risk Assessment (FRAX^®^), Garvan Fracture Risk Calculator (FRC), Q-fracture, Osteoporosis Self-assessment Tool (OST).; KQ 2: Risk factors for osteoporosis (eg, medication use, smoking, body mass index) or clinical risk assessment or fracture risk prediction tools.; KQ 3: System-level approaches targeting provider behaviors or systems operations to optimize uptake of osteoporosis screening:; - Clinical and patient reminder systems; - Bone health clinics; - Provider education; - Targeted/tailored or bidirectional patient education such as an interactive voice response (IVR) assessing individual risk scores or system-level algorithm deployed for patient identification; - Remote consultation (eg, ECHO^17^); - Nurse/physician/pharmacist-led interventions; - Clinician incentives; - Academic detailing; - Patient self-referral system | KQ 1, KQ 2: Drug treatment trials; diagnostic testing in symptomatic populations; KQ 1: Independent risk factors, additional imaging technologies; KQ 3: Generic patient or health education that has not been customized on individual patient factors such as age, screening history, or risk (eg, generic mailed pamphlet, mass awareness campaigns)
Comparator | KQ 1, KQ 2: Other risk assessment tools, bone mineral density testing via validated approach (eg, dual-energy x-ray absorptiometry [DXA]).; KQ 3: Usual care, other system-level approaches, patient-focused interventions. | Studies with no comparator
Outcomes | KQ 1, KQ 2: Fracture rates; BMD with osteoporosis (T-score ≤ −2.5) or osteopenia (T-score between −1.0 and −2.5) plus additional risk factor.; KQ 3: Fracture rates, osteoporosis screening rates. | None
Timing | KQ 1, KQ 2: Any timing; KQ 3: Longitudinal, prospective | KQ 3: Cross-sectional
Setting | KQ 1, KQ 2, KQ 3:; - Outpatient general medical settings (eg, geriatrics, family medicine, general internal medicine, integrative medicine, urgent care, emergency departments).; - Inpatient health care setting. | KQ 3: Non-health care setting (eg, churches, pharmacies not integrated into a health care setting, senior centers)
Design^b^ | KQ 1, KQ 2: Cohort studies, case-control studies, cross-sectional studies.; KQ 1, KQ 2, KQ 3: EPOC criteria studies^b^ that have prospective data collection:; - Randomized trials; - Nonrandomized trials; - Controlled before-after studies; - Interrupted time-series studies or repeated measures studies; KQ 1, KQ 2, KQ 3: Patient-level meta-analysis | - Self-described pilot studies without adequate power to assess impact of intervention on outcomes; - Studies of small sample sizes (n < 100); - Not a clinical study (eg, editorial, non-systematic review, letter to the editor); - Uncontrolled clinical study; - Qualitative studies; - Clinical guidelines; - Systematic reviews (only to be scanned for relevant primary studies)
Countries | OECD^c^ | Non-OECD
Language | English abstract | No English abstract
Years | Any | None
Publication types | Full publication in a peer-reviewed journal | Letters, editorials, reviews, dissertations, meeting abstracts, protocols without results

Abbreviations BMD=bone mineral density; DXA=dual-energy x-ray absorptiometry; FRAX=Fracture Risk Assessment tool; FRC=Fracture Risk Calculator; IVR=interactive voice response; KQ=Key Question; MOST=male osteoporosis screening tool; MORES=male osteoporosis risk estimation score; OECD=Organization for Economic Co-operation and Development; OST=Osteoporosis Self-assessment Tool

a Special populations with high risk for osteoporosis were considered for exclusion based on screening guidelines from National Osteoporosis Society and Endocrine Society.

b See Cochrane EPOC criteria for definitions and details.^13^

c Organization for Economic Co-operation and Development includes Australia, Austria, Belgium, Canada, Chile, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Lithuania, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, United States.

## DATA ABSTRACTION

Data from published reports were abstracted into a customized DistillerSR database by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus was not reached. Data elements included descriptors to assess applicability, quality elements, intervention/exposure details, and outcomes.

Key characteristics abstracted included patient descriptors (eg, age, race, Veteran status, comorbidities). For KQ1 and 2, risk assessment tool or risk factors, cutpoints reported per tool for sensitivity and specificity analysis (eg, OST score < 2), reference population used for BMD T-score calculation (eg, race and gender specific NHANES III), and region of interest for DXA scan (eg, lumbar spine, femoral neck, nondominant forearm) were abstracted. Abstracted study characteristics for KQ 3 included intervention details (eg, intervention target, duration/intensity, key intervention components), comparator, and outcomes, as described in Table 1. Multiple reports from a single study were treated as a single data point, prioritizing results based on the most complete and appropriately analyzed data. When critical data were missing or unclear in published reports, we requested supplemental data from the study authors.

For KQ 1 and KQ 2, outcomes of interest were primarily reported as test characteristics of screening tools and were abstracted as reported, including area under the curve (AUC), sensitivity/specificity, odds ratios, and observed/expected ratios. AUC conveys the degree to which a tool can discriminate between 2 clinical states (at risk or not at risk),^18^ where an AUC of 0.5 is considered no better than chance and AUC of 1 perfectly distinguishes between at risk and not at risk. Within these limits, an AUC of 0.7 to 0.8 is acceptable discrimination and 0.8 to 0.9 is excellent.^19^ Observed/expected ratios or odds ratios were abstracted for those studies evaluating individual risk factors or that did not report AUCs or sensitivity and specificity. The observed/expected ratio indicates the extent to which a given population experiences the condition in question (ie, osteoporosis or fracture) in relation to what would be expected based on the prediction from a given risk assessment tool.

For details of study characteristics, see Appendices B and C. Appendices D and E list excluded studies and the reason for exclusion.

## QUALITY ASSESSMENT

Quality assessment was done by the investigator abstracting or evaluating the included article and was over-read by a second, highly experienced investigator. Disagreements were resolved by consensus between the 2 investigators or, when needed, by arbitration by a third investigator.

We used the Cochrane EPOC risk of bias (ROB) tool for KQ 3, which is applicable to randomized, nonrandomized, controlled before-after, and interrupted time-series studies.^13^ These criteria are adequacy of randomization and allocation concealment; comparability of groups at baseline; blinding; completeness of follow-up and differential loss to follow-up; whether incomplete data were addressed appropriately; validity of outcome measures; protection against contamination; selective outcomes reporting; and conflict of interest. Summary risk of bias ratings include “low risk of bias,” “unclear risk of bias,” and “high risk of bias.”

We assigned a summary risk of bias score (“low risk of bias” or “at risk of bias”) to individual studies using the QUADAS-2 for Diagnostic Accuracy Studies.^20^ The criteria are patient selection, concerns about the index test, the gold standard, and patient flow and timing. For cohort and case-control studies, we used the modified Newcastle-Ottawa scales.^21^ This scale includes quality assessment criteria for selection of cases and controls, comparability of cases and controls, and ascertainment of exposure (or outcome as relevant). Summary risk of bias rating for the Newcastle-Ottawa scales include “low risk of bias,” “unclear risk of bias,” and “high risk of bias.”

## DATA SYNTHESIS

We summarized the primary literature using relevant data abstracted from the eligible studies. Summary tables describe the key study characteristics of the primary studies: study design, patient demographics, and details of the intervention and comparator, risk assessment tool or risk factors. We then determined the feasibility of completing a quantitative synthesis (ie, meta-analysis) to estimate summary effects. For meta-analyses, feasibility depends on the volume of relevant literature (ie, at least 3 studies reporting the same outcome), conceptual and statistical homogeneity (ie, I^2^ < 90%) of the studies, and completeness of results reporting.

We aggregated outcomes when there were at least 3 studies with the same outcome, based on the rationale that 1 or 2 studies do not provide adequate evidence for summary effects. For KQ 3, we grouped outcomes into similar intervention types (eg, patient-focused, provider-focused). When meta-analyses were feasible, we conducted them stratified by study design (randomized vs nonrandomized). Studies reported dichotomous outcomes and continuous outcomes. Diagnostic text accuracy outcomes were combined using AUC/ROC and sensitivity and specificity where possible. Similarly, dichotomous outcomes were combined using risk ratio or odds ratio. For analyses with few studies (n < 20), we used the Knapp Hartung approach^22^ to adjust the standard errors of the estimated coefficients. Sensitivity analyses included analyses that omit studies with patients at increased risk for osteoporosis or of interventions (KQ 3) of varying complexity. We evaluated for statistical heterogeneity using visual inspection and Cochran’s Q and I^2^ statistics. When the I^2^ test indicated considerable heterogeneity (ie, > 90%), we did not present summary estimates, based on the rationale that if 90% of the variability is attributed to study differences, the summary estimate cannot be meaningfully interpreted.

When a quantitative synthesis was not feasible, we narratively analyzed the data. We gave more weight to the evidence from higher-quality studies with more precise estimates of effect. The narrative synthesis focused on documenting and identifying patterns in efficacy across risk prediction tools (KQ 1 and KQ 2) and interventions (KQ 3), comparators, and outcome categories. We analyzed potential reasons for inconsistency in treatment effects across studies by evaluating differences in the study population, intervention, comparator, and outcome definitions.

## RATING THE BODY OF EVIDENCE

The certainty of evidence (COE) for each KQ 1 and KQ 3 was assessed using the partially contextualized approach described by the Grading of Recommendations Assessment, Development, and Evaluation (GRADE) working group.^23^ In brief, this approach requires the assessment of 4 domains: risk of bias, consistency, directness, and precision. Additional domains to be used when appropriate are coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. These domains were considered qualitatively, and a summary rating was assigned after discussion by 2 investigators (JG, AG) as high, moderate, low, or very low COE.

## PEER REVIEW

A draft version of this report was reviewed by technical experts and clinical leadership. A transcript of their comments and our responses is in Appendix F.