# APPENDIX G TOOLS

Please refer to the main report’s reference list for citations in this Appendix.

Tool | Components | Number of Studies
FRAX (with and without variation) | - Age; - Sex; - Weight; - Height; - Previous fracture; - Parental history of hip fracture; - Smoking status; - Glucocorticoid use; - Rheumatoid arthritis; - Secondary osteoporosis; - ≥3 units of alcohol per day; - Femoral neck BMD | 19 ^25^ ^,^ ^27^ ^–^ ^43^ ^,^ ^48^
OST | - Weight; - Age; Test if score < 2; 0.2× (body weight in kilograms−age in years), truncate to yield an integer | 8 ^28^ ^,^ ^29^ ^,^ ^50^ ^–^ ^54^ ^,^ ^56^
OSTA | - Test if score < 2; - 0.2×body weight in kilograms (truncate to yield an integer)−0.2× age in years (truncate to yield an integer) | 2 ^50^ ^,^ ^55^
QFracture (2009) | - Age at study entry; - Body mass index; - Smoking status (non-smoker, ex-smoker, light smoker (<10 cigarettes/day), moderate smoker (10-19 cigarettes/day), heavy smoker (≥20 cigarettes/day); - Parental history of osteoporosis or hip fracture in a first degree relative (binary variable; yes/no); - Cardiovascular disease (binary variable; yes/no); - Alcohol intake (none, trivial (<1 unit/day), light (1-2 units/day), medium (3-6 units/day), heavy (7-9 units/day), very heavy (>9 units/day); - Rheumatoid arthritis (binary variable; yes/no); - Type 2 diabetes (binary variable; yes/no); - Asthma (binary variable; yes/no); - History of falls (binary variable; yes/no); - Chronic liver disease (binary variable; yes/no); - Gastrointestinal conditions likely to result in malabsorption (that is, Crohn’s disease, ulcerative colitis, celiac disease, steatorrhoea, blind loop syndrome) at baseline (binary variable; yes/no); - Other endocrine conditions (thyrotoxicosis, primary or secondary hyperparathyroidism, Cushing’s syndrome) at baseline (binary variable; yes/no); - At least two prescriptions for systemic corticosteroids in the six months preceding baseline (binary variable; yes/no); - At least two prescriptions for tricyclic antidepressants in the six months preceding baseline (binary variable; yes/no); - At least two prescriptions for hormone replacement therapy (in women) in the six months preceding baseline (binary variable; yes/no); - Menopausal symptoms in women (binary variable; yes/no) | 5 ^30^ ^,^ ^32^ ^,^ ^40^ ^,^ ^57^ ^,^ ^58^
QFracture (updated 2016) | - Age; - Sex; - Ethnicity; - Smoking status (non smoker, ex smoker, light, moderate, heavy); - Alcohol use; - Type 1 or Type 2 diabetes; - Parental history of hip fracture/osteoporosis; - Nursing or care home residence; - History of prior osteoporotic (wrist, spine, hip, or shoulder) fracture; - History of falls; - Dementia; - Cancer; - Asthma or COPD; - Cardiovascular disease; - Chronic liver disease; - Chronic kidney disease; - Parkinson’s disease; - Rheumatoid arthritis or systemic lupus erythematosis (SLE); - Gastrointestinal malabsorption (including Crohns disease, ulcerative colitis, celiac disease, steatorrhoea, blind loop syndrome); - Epilepsy or use of anticonvulsants; - Use of antidepressants (at least 2 scripts in last 6 months); - Use of corticosteroids (at least 2 scripts in last 6 months); - Body mass index; Additional factors are used for women only:; - Use of oestrogen only Hormone Replacement Therapy; Endocrine problems (thyrotoxicosis, primary or secondary hyperparathyroidism, Cushings syndrome) | 1 ^57^
MORES | - Age; - COPD; - Weight | 4 ^27^ ^,^ ^59^ ^–^ ^61^
Garvan | - Age; - Bone mineral density; - Body weight; - A history of prior fracture after the age of 50; - Any falls during the past 12 months | 3^30,40,43^}
FRA-HS | - BMI; - Sex; - Age; - Long-term use of corticosteroids (At least 180 DDD within the year preceding the index date); - alcohol abuse (ie, >40 and >20 g daily for men and women, respectively) or alcohol-related diseases; - current smoking; - Rheumatoid arthritis; - history of osteoporotic fractures; - other causes of secondary osteoporosis | 1 ^64^
Korean Fracture Risk Score (KFRS) | - Age; - BMI; - history of recent fragility fracture; - regular exercise (Weekly exercise of one or more times); - high alcohol intake (Five or more units for men, three or more units for women); - current smoking status; - recent use of oral glucocorticoid; - history of rheumatoid arthritis; - use of medication or disease causing a low BMD | 1 ^68^
KORAM-M: Model 1 (age and body weight) | - Age; - Weight; (age in years/10)×(−3)+(weight in kilograms/ 10)×8] | 1 ^55^
KORAM-M: Model 2 (age, weight, and exercise) | - Age; - Weight; - Health behavior; [(age in years/10)×(−3)+(weight in kilograms/ 10)×8+(if no regular exercise)×(−2)] | 1 ^55^
KORAM-M: Model 3 (age, weight, exercise, vitamin D, and ALP) | - Age; - Weight; - Exercise; - Blood tests(Vitamin D & ALP); [(age in years/10)×(−3)+(weight in kilograms/ 10)×8+(if no regular exercise)×(−2)+(if low vitamin D)× (−2)+(if elevated ALP)×(−6)] | 1 ^55^
FRC | - Age; - Sex; - Race/ethnicity; - BMI; - BMD; - Smoking, current; - Alcohol >3 units/day Glucocorticoid exposure Fracture after age 45 y; - Parent with hip fracture Rheumatoid arthritis Secondary cause of bone loss; Specific patient characteristics (body mass index [BMI], history of fracture, parental history of hip fracture, smoking and alcohol consumption, use of corticosteroids, prevalence of rheumatoid arthritis, and secondary osteoporosis) are compared with the base population and relative risks are applied to factors that differ between the individual patient and the base population. Race/ethnicity offsets are based on published fracture risk ratios relative to Caucasian. Data on age, gender, race, and BMI are required. | 1 ^66^
Model 1: low body weight and age >65 | - Low body weight; - Age of >65 yr | 1 ^52^
Model 3: OST + low body weight and age >65 | - Low body weight; - Age of >65 yr; - OST score, per 1 unit increase | 1 ^52^
FRAX-A | - Age; - Sex; - Prior fracture; - COPD diagnosis (smoking proxy); - Prolonged glucocorticoid use; - Rheumatoid arthritis diagnosis; - Secondary osteoporosis; - Alcohol/substance abuse (high alcohol use proxy) | 1 ^41^
FRAX-A+ | - Age; - Sex; - Prior fracture; - COPD diagnosis (smoking proxy); - Prolonged glucocorticoid use; - Rheumatoid arthritis diagnosis; - Secondary osteoporosis; - Alcohol/substance abuse (high alcohol use proxy); - Aggregated Diagnostic Groups score; - Number of hospitalizations, three years prior to BMD test; - Depression diagnosis; - Dementia diagnosis | 1 ^41^
Model II: age+baseline weight+prior fracture+fall | - Age; - Baseline weight; - Prior fracture; - Fall | 1 ^63^
e-FRAX | - Prior fracture; - Age ≥ 80 years; - Normal or underweight versus overweight; - Malnutritive disorder; - Opioid exposure; - Proton-pump inhibitor (PPI) use; - Depression diagnosis; - Stroke; - Smoking; - Seizure disorder; - Alcohol abuse disorder; - 6–12 clinic visits in prior year versus 5 or fewer; - 13+ clinic visits in prior year versus 5 or fewer; - Fall risk | 1 ^28^
VA-FARA | - Age; - Sex; - BMI; - Previous fracture; - History of parental hip fracture; - Current smoking; - Glucocorticoids; - Rheumatoid arthritis Alcohol use; - BMD (optional) | 1 ^28^
“Modified FRAX” (without BMD) | - Age; - Race/ethnicity limited to categories utilized in FRAX (white, black, Asian, Hispanic); - Weight (kg); - Height (cm2); - History of previous fragility fracture; - Ever glucocorticoid use; - Rheumatoid arthritis; - Alcohol use | 1 ^26^
Mscore | - Age; - Weight; - Gastrectomy; - Emphysema; - Prior fractures; [2 × (patient age in decades) - (weight in lb/10) + 4 if gastrectomy, + 4 if emphysema, + 3 if two or more prior fractures + 14] | 1 ^67^
Weight-based calculation | Weight | 1 ^51^
BMI-based calculation | Weight in kilograms divided by height in meters squared | 1 ^51^