# APPENDIX F PEER REVIEW COMMENTS

Question Text | Reviewer Number | Comment | Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes
Are the objectives, scope, and methods for this review clearly described? | 2 | Yes
Are the objectives, scope, and methods for this review clearly described? | 3 | Yes
Are the objectives, scope, and methods for this review clearly described? | 4 | Yes
Are the objectives, scope, and methods for this review clearly described? | 5 | Yes
Are the objectives, scope, and methods for this review clearly described? | 6 | Yes
Are the objectives, scope, and methods for this review clearly described? | 7 | Yes
Are the objectives, scope, and methods for this review clearly described? | 8 | Yes
Is there any indication of bias in our synthesis of the evidence? | 1 | No
Is there any indication of bias in our synthesis of the evidence? | 2 | No
Is there any indication of bias in our synthesis of the evidence? | 3 | No
Is there any indication of bias in our synthesis of the evidence? | 4 | No
Is there any indication of bias in our synthesis of the evidence? | 5 | No
Is there any indication of bias in our synthesis of the evidence? | 6 | No
Is there any indication of bias in our synthesis of the evidence? | 7 | No
Is there any indication of bias in our synthesis of the evidence? | 8 | No
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 1 | No
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 2 | No
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 3 | No
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 4 | No
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 5 | Yes: Recent article in Journal of Clinical Densitometry on use of OST in Irish Men (J Carey senior author) | Thank you. This study would not meet eligibility criteria. Vertebral fracture scanning would be an “additional imaging technology” and not a triage tool for identifying people who should be sent on to imaging (e.g., DXA, VFA scan).^124^
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 6 | No
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 7 | No
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 8 | No
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | The review was comprehensive and focused and addressed the question. As noted in my review [copied below], it is definitive. | Acknowledged
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | The ESP was a comprehensive review of the literature on screening tools for male osteoporosis. From my perspective it will enable an informed discussion on the issue of which tools to consider for identification of older men at higher osteoporosis risk, and thus subsequent bone density testing. | Acknowledged
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | The presentation was superb. | Acknowledged
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Thank you for this excellent and thorough report. Some suggestions regarding clarity and readability below. | Acknowledged
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Major; 1. In introduction, would justify why the key questions are among men not identified by prior fracture (i.e., guideline consensus that these individuals should be tested/treated) | Language describing that the goal of this review is centered around primary prevention has been added to the introduction of the main report and the executive summary. We have also added language to the study eligibility sections describing the potential for enriching the study population with high numbers of fractures.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | 2. The authors report a very large range of AUCs for the tools described, likely due to study heterogeneity. It would be useful to add a qualitative description of which population(s) had excellent vs. poor discrimination if possible. | The range of AUCs is likely due to multiple variables. While some of these are population-based, heterogeneity is also driven by some of the methodological choices in the individual studies that are not easily explained via population variables only.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | a. Specifically describing evidence and/or gaps in underrepresented racial and ethnic groups would be appropriate in the summary | Thank you for this comment. We have added some contextualizing statements about race/ethnicity in the results sections and the evidence gaps sections.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | 3. When you discuss the ability of tools to predict “osteoporosis”, please confirm how this was defined. By DXA only, by FRAX threshold to treat OP, including low trauma hip/vertebral fractures? | Thank you. We defined osteoporosis as BMD T score ≤ −2.5 and osteopenia as BMD T score between −1.0 and 2.5 in the study selection section of the executive summary.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | 4. Page 68 – would not repeat the same introductory paragraphs in the discussion as in the prior sections. Would like to see more synthesis of findings, clinical/policy suggestions, research gaps described here. | Thank you for this suggestion, we have reduced the redundancy in the first paragraphs of the summary and discussion section and added some future research and clinical context.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Minor; 1. Table 16 – not clear why “Antipsychotic use on risk of fracture” is listed in the outcomes category; shouldn’t this be a special population? Why just antipsychotics and not other medications where evidence is conflicting and use is high in VA (e.g., opiates, gabapentinoids) | Thank you. We have added these as examples of special populations of interest.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | 2. Table 17 – isn’t “Limited studies conducted with average risk male only populations” just a subset of “Limited studies conducted with male only populations”? Why are both listed? Is the point that evidence is needed separately for average and high-risk populations? | Thank you. We have clarified that there are limited studies with average-risk men and with men at elevated risk (eg, ADT).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | 3. Throughout the manuscript, there is frequent use of “eg” or “ie” followed by lists, instead of the standard “e.g.,” and “i.e.,” | Thank you, this is the ESP style for the use of these items.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | 4. Page 2: please clarify if there was an I2 cutpoint for conducting meta-analysis; <90% is still very high | Thank you, this language is in our methods section (data synthesis section of the methods, paragraph 2)
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | 5. Page 3 typo - “impact the easy” rather than “impact the ease” | Thank you. We have resolved this typo.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | 6. Page 4 typos/grammar issues in sentence “Clinical decision support tool that combine tailored risk-based education for patients and tailored provider recommendations at the point of clinic visit showed promise but were only evaluated in 1 study. .” | Resolved.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Overall an impressive manuscript with good summaries of findings, risk of bias and certainty of evidence. Thanks to the authors for their dedication in producing this paper! | Thank you. We appreciate this comment.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Within the Executive Summary and the Introduction, please provide more information related to the sentence “Veterans of both sexes are at higher risk of osteoporotic fracture than civilians.” I recommend an overall summary (1 paragraph) of the rate of fracture, along with relevant citations. | Thank you for this suggestion. We have revised the Executive Summary per your suggestion and have included citations in the introduction section.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | I understand why you are excluding men with prior fracture from your literature search, but the general person reading this summary might not. Thus, please explain this approach within the Executive Summary and Introduction. | Thank you for this suggestion. See the response to a similar comment above.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 1 line 19, suggest adding a comma between “how to screen men” and “when screening is warranted” | Resolved.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 1 line 26: focuses on individuals at high risk of fracture who do not have BMD defined osteoporosis. Would therefore delete the phrase “at high risk of osteoporosis.” | Thank you, we have removed “high risk of osteoporosis” from the second paragraph of the introduction to the executive summary
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 7 line 43: Given the focus of this report, please dedicate some space to summarizing the data demonstrating that veterans have more fragility fractures than civilians. | Thank you for this suggestion. We have added this information.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 9: please explain how disagreement was resolved. Was a 3rd party involved? | Thank you, we added details about how disagreements were resolved (ie, via consensus or third investigator) to the study selection section of the executive summary and main report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 9: please add a sentence and citation, describing validity of the Distiller AI | Thank you for this suggestion. Two sentences on the validity of the DistillerAI citing an AHRQ report on the topic have been added to the study selection section of the methods in the main report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 19 table 2: Should state “number of subjects” | Thank you. We added “number of participants” to the total N row of the Evidence Profile table.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Figures 3, 4, 5, 7, 8, 9: recommend adding summary statistic for AUC to each Forest plot (similar to that reported in Figure 6). | Thank you for this comment. We have presented summary estimates when possible given statistical homogeneity (ie, I^2^ < 90%). Further details and rationale have been added to the data synthesis section of the executive summary and main report body.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 31: Line 11 seems to contain a typographical error since the AUC is reported as 77.8. Did you mean 0.778? | Thank you, this error has been corrected.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | The International Society for Clinical Densitometry guidelines state: “Use a uniform Caucasian (non-race adjusted) female reference for men of all ethnic groups.*” Thus it is critical to note which of the studies cited in this tome are an exception to that guideline. As it stands now, the only paper in which this issue is mentioned is by Sinnott (128 Black veterans) on page 37. | Thank you, information on the reference standards used for each study has been added to the KQ 1 and KQ 2 study characteristics appendix table where applicable. We have also added details of the ISCD guidelines on reference standards to the study selection section of the main report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 42 line 12-13: “for these outcomes (see Table 4)” should end with a period, not a comma The title for Table 4 mentions fracture as one outcome of the studies cited. However in the Table, no studies used fracture as an outcome. I suggest deleting “fracture” from the title. | We have rewritten this sentence to improve clarity.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 43: In my opinion it seems reasonable to exclude the osteomyelitis study from this review. Clinicians don’t consider osteomyelitis to be a risk factor for osteoporosis, and given the number of excluded veterans I question whether this would be a valid study. | This study fits our eligibility criteria. However, we agree that this study is of questionable quality (ie, high rate of missing data). We rated the risk of bias for this study as “at risk”.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 43 and related: I was surprised that there were no studies investigating the risk of osteoporosis among veterans with COPD. | Agreed. This is interesting. However, many of the included studies may have included COPD as a proxy for smoking status.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Table 10: Patient navigation. Was the second study excluded from the table because it focused on women? Suggest adding the study, since KQ3 is not restricted to men. | Thank you. We have added this study to Table 10.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 72 line 47: should state “studies” rather than “students” | Corrected.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 73 line 7: Currently states “Among an average risk in the male Veteran population, FRAX and OST were the most common tools assessed for predicting fracture and/or osteoporosis”. Suggest revising this to state “Among male Veterans at average risk of osteoporosis and/or fracture, FRAX and OST were assessed most often.” | We have made the suggested change.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 76 line 12: calcaneal is misspelled | Corrected.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 76 line 21: DXA is spelled “DAX” | Corrected.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 82 line 19: currently states “Tools predicting hip fracture or MOF, each tool also displayed heterogenous AUCs..” and is confusing. Suggest changing the sentence to something like: “Tools such as FRAX, QFracture and Garvan display poor to excellent discrimination in predicting hip fracture and MOF” | Thank you for this suggestion. The language in the conclusion section has been changed.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | Page 82 line 23: “approached” should be “approaches” | Corrected.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | In the final sentences, could you go back to the overall risk of osteoporosis and fracture in male veterans, and provide advice to the general clinician? As Veterans Affairs health care providers, do you screen your men for osteoporosis? At our Madison Wisconsin VA, there is no barrier to screening so any man who is referred, gets screened. Despite the fact that there is not great data on whether to screen male veterans for osteoporosis, the general practitioner needs guidance. | Thank you for this comment. We have further contextualized of finding in the Clinical Implications section.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - General themes; ○ I wonder if more time should be spent clarifying that osteoporosis is based on T-scores (not fx) which as stated in certain places had a change of reference group (sex/race matched vs. white females) throughout this timeline. Although part of the questions- it might be helpful to clarify that this osteoporosis definition does NOT include clinical osteoporosis by prior fracture. | Thank you for suggesting this clarification. Further context for the definition of osteoporosis and osteopenia via BMD T-score has been added to the study selection section of the main report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - Page 1; ○ Line 37- sentence confusing- are these patient-important outcomes?; ▪ Also missing punctuation | Resolved.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - Page 3; ○ Line 46- “easy” should be “ease”; ▪ Also unclear if this statement about deployment of these tools within the VA is necessary. | Resolved.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - Page 4; ○ Line 50 extra punctuation; ○ Line 52- Sentence confusing. May be aided by defining fixed appointments. | Thank you. We have revised this sentence to provide better clarity.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - Page 5; ○ Line 13- may want to say the OST had the “least amount of variables” rather than “relatively few”. Or just define the # of variables. | Thank you, this change has been made.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - ○ Line 21- should it be clarified which outcomes we are discriminating between? BMD and Fracture? | Thank you, the outcomes have been clarified in the key findings section of the executive summary discussion.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - ○ Line 25- from above summary (pg4) it appears that patient-focused targets more often associated with increased screening uptake? I don’t see clearly where combined patient/provider interventions have highest impact. Please clarify. | We have revised this section to improve clarity.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - Page 6; ○ Line 25- just say that OST has 2 variables.; ○ Line 40- extra space | Thank you, this has been addressed.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - Page 21; ○ Line 36- OST = 2variables (same suggestion as above) | Thank you, this has been addressed.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - Page 22; ○ line 41- define prevalence. % or in 1,000? | Thank you, the prevalence of fracture has been marked as a percentage of the study population’s results section of the KQ 1.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - Line 53- extra underline at the end “_The 2” | Thank you, this has been addressed in the final report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - Page 23; ○ Tables- define denominator for prevalence. I generally don’t think of it as a pure % esp w/ rare outcomes. | Thank you, the prevalence of fracture has been marked as a percentage of the study population’s results section of the KQ 1.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - ○ Line 60- extra underline “(Figure 5)” | Thank you, this has been addressed in the final report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | | - ○ Again- Prevalence rate is not a term I have seen used (although I see it is a true term). Consider denominator. | Thank you, we have changed the prevalence rate to prevalence in the results section of KQ 1.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | It is disappointing that the literature review ended in mid-2019 but the report was finished in late 2021. I hope that other studies were not missed by this (in addition to the recent one listed above). | Acknowledged. We updated the search and integrated new studies for the final report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | In the discussion, it would have been interesting to cite a similar review of screening in women - to compare how some of the same tools (e.g. FRAX, Garvan, OST) worked in women compared to men. Are the disappointing results in men so different from what we seem to accept less critically in women? The SCOOP Study (Shepstone et al.) is very recent, showing the efficacy of FRAX in women. Finally, the tools to predict osteoporosis by DXA were studied mostly using the male normative database for the definition of osteoporosis, whereas FRAX uses the white female database for all. This may change the discrimination of the various tools to identify osteoporosis by DXA. Finally, it is not surprising that system interventions to improve osteoporosis screening in men have failed, as have most osteoporosis interventions in women. | Thank you, we have added reference to the SCOOP study in the Clinical Implications section.; The comment was added to the KQ1 summary discussion on page 78.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | The contribution of each author should be provided. | Thank you for this suggestion, we have updated the authorship section to include contributions.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | I am not aware of any publications that were not identified through the literature search. All the papers that I know on the subject are included. | Acknowledged
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | See email for comments a paper that is listed incorrectly in PubMed. First author for reference #50 is listed as Steuart Richards J. The correct name should be Richards JS as in reference #53 - See attachment | Thank you for bringing this indexing error to our attention. We have made the changes in our citation manager and corrected the name as referenced in our figures and text.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | The authors have performed a comprehensive and clearly articulated review addressing the three clinical questions pertaining to osteoporosis and fracture risk identification tools in men and in Veterans, as well as interventions that increase screening/primary prevention of osteoporosis. My comments are summarized below. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | 1. For Key Question 1: I realize the focus of this question is on tools and does not include risk factors. It seems confusing to apply FRAX to those with ADT as existing guidelines recommend DXA screening to be obtained in people on chronic ADT, as this is an established risk factor for osteoporosis by DXA and fragility fracture, similar to chronic steroids. In this case, the ADT alone, would be the risk factor prioritizing the patient for DXA. The FRAX would be applied after DXA result is obtained to help determine treatment indication. Is the goal of key question 1 and 2 to identify the evidence for clinical risk tools and/or risk factors that identify patients at highest risk of osteoporosis or major fracture in order to facilitate prioritization of screening with DXA? Or treatment without DXA? Or both? | Thank you for this clarification. The purpose of KQ 1 and 2 was to determine how best to identify those at the highest risk for fracture (which includes patients with osteoporosis).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | 2. The paragraph on page 30 describing the Williams, et. al. study lists the risk factors for VA-FARA incorrectly. The factors listed are those for e-FRAX. The risk factors for VA-FARA include prior fracture, age>80, underweight, malnutrition, opioid exposure, proton-pump inhibitor use, depression diagnosis, stroke, seizure disorder, alcohol abuse disorder, fall risk, and clinic visits in prior year (Osteoporos Int (2012) 23:1017–1027). Technically, the VA-FARA and FRAX tools do identify those with prior fracture and are designed to predict fracture risk over osteoporosis by DXA, and the OST does not include prior fracture and is more useful for predicting osteoporosis by DXA scan. | Thank you, we have corrected this in the text.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | 3. For Key Question 3: The authors limited studies to randomized, non-randomized, controlled before-after, and interrupted time-series studies to reduce problems with study quality, publication bias and risk for confounding. However, it is possible that some observational studies might be more directly applicable to the population of interest and may reflect a more real-life setting than RCTs. Have the authors considered including some observational studies for Key Question 3? An observational cohort study published in the Journal of Primary Care & Community Health 2017, Vol. 8(3) 135–140 saw significantly increased rates of DXA screening in US Veterans through a systems redesign approach utilizing a bone health team telephone clinic dedicated to screening and managing Veterans in primary care panels. | We appreciate this comment and affirm the value of other study designs. As in all systematic reviews, we make methodological choices to balance rigor, responsiveness to questions of interest, and feasibility to complete the review. Thus, we constrained eligibility for KQ 3 to studies designs best suited to assess the effectiveness of system-level interventions as outlined by the Cochrane Effective Practice and Organization of Care (EPOC) Group.