# APPENDIX E KQ 3 EXCLUDED STUDIES

Study | Exclusion Reason
| Population | Intervention | Outcomes | Comparator | Design | Setting | OECD
Abdulameer, 2017^1^ | | | X
Adebajo, 2006^2^ | | | | X
Adler , 2003^3^ | | X
Ahmed, 2012^4^ | X
Ashe, 2004^5^ | X
Axelsson, 2016^6^ | X
Bahrs, 2008^7^ | X
Baker, 2011^8^ | | | X
Barrack, 2009^9^ | X
Barry, 2007^10^ | | | | X
Ben Sedrine, 2004^11^ | | | | X
Berarducci, 2002^12^ | | | | X
Berggren, 2008^13^ | X
Binaghi, 1993^14^ | | X
Birks, 2004^15^ | | X
Blake, 2009^16^ | | | | | X
Blau, 2003^17^ | X
Bowen, 2018^18^ | | | | | X
Bruyere, 2008^19^ | X
Buist, 2004^20^ | | | | | X
Bultijnck, 2018^21^ | | | | | X
Bunta, 2016^22^ | X
Cadarette, 2011^23^ | | X
Cameron, 2011^24^ | | X
Carceller, 2015^25^ | | X
Chan, 2012^26^ | | X
Chan, 2015^27^ | | | | X
Chan, 2018^28^ | | X
Chang, 2011^29^ | | X
Chang, 2017^30^ | | | | | | | X
Chen, 2006^31^ | | | | | | X
Chen, 2009^32^ | | X
Chitre , 2008^33^ | | X
Ciaschini, 2010^34^ | X
Clark, 2012^35^ | X
Collinge, 2008^36^ | | | | X
Compston, 2016^37^ | | | | X
Cooper, 2006^38^ | X
Cox, 2008^39^ | | | | | | X
Cram, 2006^40^ | | X
Cram, 2016^41^ | | X
Crockett, 2008^42^ | | | | | X
Curry, 2002^43^ | | X
D’Alesio, 2011^44^ | | X
Danila, 2016^45^ | X
Davis, 2000^46^ | | | | X
Daya, 2016^47^ | | X
Demark-Wahnefried, 2007^48^ | | X
Dewing, 2013^49^ | | | | | X
Dobson, 2013^50^ | X
Dore, 2013^51^ | X
Dugard, 2010^52^ | | X
Edmonds, 2016^53^ | | | X
Edwards, 2011^54^ | X
Elias, 2011^55^ | X
Elliott, 2002^56^ | | | | X
Elliott, 2002^57^ | | | | X
Elliott, 2011^58^ | | | | | X
Eyigör, 2008^59^ | | X
Feskanich, 1997^60^ | | X
Fournier, 2017^61^ | | X
Freedman, 2007^62^ | X
Gadkaree, 2015^63^ | | X
Ganda, 2014^64^ | X
Gardner, 2002^65^ | X
Gardner, 2005^66^ | X
Genuis , 2012^67^ | | X
Giannini, 2018^68^ | X
Giusti, 2009^69^ | X
Glidewell, 2015^70^ | | X
Goldshtein, 2020^71^ | | | | X
Gomez, 2019^72^ | | | | X
Gonnelli, 2005^73^ | | X
Goode, 2017^74^ | X
Gossec, 2019^75^ | X
Greene , 2010^76^ | | | | | X
Greenspan, 2012^77^ | X
Gupta, 2018^78^ | X
Hall, 2009^79^ | X
Hansen, 2007^80^ | | | | | X
Hansma, 2010^81^ | | | | | X
Hawker, 2003^82^ | X
Hawley, 2016^83^ | X
Heilmann, 2012^84^ | X
Hess, 2013^85^ | | | X
Ho, 2006^86^ | X
Hodsman, 2004^87^ | | X
Hofflich, 2014^88^ | X
Hudson, 2011^89^ | | | | X
Huntjens, 2011^90^ | X
Huntjens, 2011^91^ | X
Iki, 2009^92^ | | X
Inderjeeth, 2010^93^ | X
Ioannidis, 2008^94^ | | | | | X
Irwin, 2014^95^ | X
Izuora, 2011^96^ | | X
Jaglal, 2009^97^ | X
Jensen, 2012^98^ | | X
Jiang, 2016^99^ | | X
Jones, 2011^100^ | X
Joy, 2000^101^ | X
Kastner, 2010^102^ | | | | X
Kennedy, 2015^103^ | | | X
Kesman, 2010^104^ | | | | | X
Kim, 2016^105^ | X
Kimber , 2009^106^ | | | | X
Kirk, 2002^107^ | | | | X
Kruger, 2013^108^ | | | | | | | X
Kuczynski , 1989^109^ | | | X
Lakatos, 2014^110^ | | X
Laliberte, 2010^111^ | | | | | X
Laslett, 2007^112^ | X
Laufer, 2014^113^ | | | | X
Law , 2005^114^ | | | X
Lee, 2007^115^ | X
Lee, 2016^116^ | X
Lee, 2020^117^ | | X
Leeangkoonsathian, 2012^118^ | | | | | | | X
Leslie , 2011^119^ | | X
Leslie, 2010^120^ | | X
Lin, 2007^121^ | | | | | | | X
Long, 2010^122^ | | | | | X
Lord, 1996^123^ | | X
Lovric , 2016^124^ | | X
Lufkin, 1998^125^ | X
Lukert, 2011^126^ | | X
MacIntyre, 2019^127^ | | | | | X
MacLaughlin, 2005^128^ | | | | X
Magill-Lewis, 2006^129^ | | | | | X
Majumdar, 2004^130^ | X
Majumdar, 2007^131^ | X
Majumdar, 2008^132^ | X
Majumdar, 2010^133^ | X
Majumdar, 2011^134^ | X
Malgo, 2016^135^ | X
Mastaglia, 2005^136^ | X
Merchant, 2010^137^ | X
Merz, 2006^138^ | | X
Mosekilde, 1999^139^ | | X
Nakamoto, 2008^140^ | | X
Naunton, 2004^141^ | | | X
Navarro, 2011^142^ | X
Nelson, 2014^143^ | | | | | X
Nendaz, 2005^144^ | | | | | X
Newman , 2001^145^ | | | | X
O’Brien, 2015^146^ | X
Oh, 2012^147^ | | | | | X
Olegario, 2008^148^ | | | | | X
O’Neil , 2007^149^ | X
O’Neill, 1995^150^ | | X
O’Neill, 1995^151^ | | X
Orimo, 2017^152^ | | X
Parri, 2015^153^ | X
Patel, 2010^154^ | X
Penning-van Beest, 2006^155^ | | X
Peris, 1995^156^ | | X
Peters, 2006^157^ | | | | | X
Pezzotto, 2010^158^ | | X
Pfimlin, 2019^159^ | X
Pluijm, 1999^160^ | | | | X
Polinski, 2005^161^ | | | | X
Prihar , 2008^162^ | | | | | X
Puisto, 2011^163^ | X
Radford, 2014^164^ | | X
Rapp, 2016^165^ | | | | | X
Ravn, 2002^166^ | | | | | X
Rencken, 1991^167^ | X
Reuben, 2017^168^ | | | | | X
Rucker, 2006^169^ | X
Ryder, 2012^170^ | | X
Saadi, 1999^171^ | | X
Şahin, 2013^172^ | X
Sale, 2010^173^ | X
Salovaara, 2010^174^ | | X
Salvig, 2016^175^ | | | | | X
Schmajuk, 2010^176^ | | X
Schoon, 2011^177^ | X
Schousboe, 2005^178^ | | | X
Schousboe, 2005^179^ | | X
Seuffert, 2016^180^ | | X
Sheffet, 2006^181^ | X
Shu, 2009^182^ | | | X
Sikon, 2006^183^ | | X
Solomon, 2005^184^ | | | | | X
Solomon, 2006^185^ | | | X
Stock, 1998^186^ | | | | | X
Summers , 2005^187^ | | | | X
Talalaj, 2005^188^ | | X
Tamburino , 1990^189^ | X
Torgerson, 1993^190^ | | | | | X
Tsang, 2018^191^ | | | | | X
Unni, 2015^192^ | | X
Uusi-Rasi, 2012^193^ | | | | | X
van Boven, 2014^194^ | | X
van Helden, 2007^195^ | X
Varacallo, 2013^196^ | X
Vogel, 2006^197^ | | X
Wang, 2008^198^ | | | | | | | X
Warriner , 2009^199^ | | X
Warriner, 2015^200^ | | | X
Warshaw, 2013^201^ | | | | | X
Werner , 2002^202^ | | X
Werner, 2003^203^ | | X
Wolinsky, 2017^204^ | | | X
Woltman , 2010^205^ | X
Wong, 2004^206^ | X
Woo, 2004^207^ | | | | X
Wu, 2014^208^ | | | X
Wyshak, 2010^209^ | | X
Yi, 2014^210^ | | | | | | | X
Yuksel, 2006^211^ | | X
Zhang, 2012^212^ | | | | | | | X
Zisblatt, 2013^213^ | | | | | X
Zwart, 2011^214^ | | X

## REFERENCES TO APPENDIX E

1 Abdulameer AH, Syed Sulaiman SAB, Dawood OT, AbdulRazzaq HA, Jasim HH. Assessment of Osteoporosis Knowledge Among Warfarin Users and Healthy People in the State of Penang. Clinical Medicine Insights: Therapeutics. 2017;9.
2 Adebajo A, Campbell L, Hitchcock J. Evaluating a nurse-led DXA scanning service. Nurs Stand. 2006;20(51):35–39.
3 Adler RA, Hochberg MC. Suggested Guidelines for Evaluation and Treatment of Glucocorticoid-Induced Osteoporosis for the Department of Veterans Affairs. Arch Intern Med. 2003;163(21):2619–2624.14638562
4 Ahmed M, Durcan L, Beirne JO, Quinlan J, Pillay I. Fracture liaison service in a non-regional orthopaedic clinic a cost-effective service. Ir Med J. 2012;105(1).
5 Ashe M, Khan K, Guy P, . Wristwatch-distal radial fracture as a marker for osteoporosis investigation: a controlled trial of patient education and a physician alerting system. J Hand Ther. 2004;17(3):324–328.15273672
6 Axelsson KF, Jacobsson R, Lund D, Lorentzon M. Effectiveness of a minimal resource fracture liaison service. Osteoporos Int. 2016;27(11):3165–3175.27230521
7 Bahrs C, Turk A, Eingartner C, Weise K, Rolauffs B, Stuby F. [Evaluation of a strategy for the management of accompanying osteoporosis after inpatient treatment of fragility fractures]. Z Orthop Unfall. 2008;146(1):52–58.18324582
8 Baker DW, Persell SD, Kho AN, Thompson JA, Kaiser D. The marginal value of pre-visit paper reminders when added to a multifaceted electronic health record based quality improvement system. J Am Med Inform Assoc. 2011;18(6):805–811.21659446
9 Barrack CM, McGirr EE, Fuller JD, Foster NM, Ewald DP. Secondary prevention of osteoporosis post minimal trauma fracture in an Australian regional and rural population. Aust J Rural Health. 2009;17(6):310–315.19930197
10 Barry PJ, Gallagher P, Ryan C, O’Mahony D. START (screening tool to alert doctors to the right treatment) - An evidence-based screening tool to detect prescribing omissions in elderly patients. Age Ageing. 2007;36(6):632–638.17881418
11 Ben Sedrine W, Ethgen O, Devogelaer JP, . Evaluation of proposals of Belgian Social Security Institute for reimbursement of bone densitometry tests. Toward a cost-effective strategy for osteoporosis screening? Aging Clin Exp Res. 2004;16(5):413–419.15636469
12 Berarducci A, Lengacher CA, Keller R. The impact of osteoporosis continuing education on nurses’ knowledge and attitudes. J Contin Educ Nurs. 2002;33(5):210–239.12269759
13 Berggren M, Stenvall M, Olofsson B, Gustafson Y. Evaluation of a fall-prevention program in older people after femoral neck fracture: A one-year follow-up. Osteoporos Int. 2008;19(6):801–809.18030411
14 Binaghi E, De Giorgi O, Maggi G, Motta T, Rampini A. Computer-assisted diagnosis of postmenopausal osteoporosis using a fuzzy expert system shell. Comput Biomed Res. 1993;26(6):498–516.8112053
15 Birks YF, Porthouse J, Addie C, . Randomized controlled trial of hip protectors among women living in the community. Osteoporos Int. 2004;15(9):701–706.14997286
16 Blake GM. Comparing BMD results between 2 similar DXA systems using the generalized least significant change. J Clin Densitom. 2009;12(3):404–406; author reply 407-410.19261497
17 Blau EM, Gordon SJ, Benton LK, Weiss TW, Chen YT. Establishment of an innovative clinic for postmenopausal women at high risk for fragility fracture. Drug Benefit Trends. 2003;15(10):41–46+C43.
18 Bowen ME, Bhat D, Fish J, . Improving Performance on Preventive Health Quality Measures Using Clinical Decision Support to Capture Care Done Elsewhere and Patient Exceptions. American journal of medical quality : the official journal of the American College of Medical Quality. 2018;33(3):237–245.29034685
19 Bruyere O, Brandi ML, Burlet N, . Post-fracture management of patients with hip fracture: a perspective. Curr Med Res Opin. 2008;24(10):2841–2851.18759997
20 Buist DS, LaCroix AZ, Brenneman SK, Abbott T, 3rd. A population-based osteoporosis screening program: who does not participate, and what are the consequences? J Am Geriatr Soc. 2004;52(7):1130–1137.15209651
21 Bultijnck R, Van de Caveye I, Rammant E, . Clinical pathway improves implementation of evidence-based strategies for the management of androgen deprivation therapy-induced side effects in men with prostate cancer. BJU Int. 2018;121(4):610–618.29194928
22 Bunta AD, Edwards BJ, MacAulay WB, . Own the bone, a system-based intervention, improves osteoporosis care after fragility fractures. Journal of Bone and Joint Surgery - American Volume. 2016;98(24):e109.28002377
23 Cadarette SM, Jaglal SB, Raman-Wilms L, Beaton DE, Paterson JM. Osteoporosis quality indicators using healthcare utilization data. Osteoporos Int. 2011;22(5):1335–1342.20577872
24 Cameron ID, Kurrle S, Quine S, . Increasing adherence with the use of hip protectors for older people living in the community. Osteoporos Int. 2011;22(2):617–626.20571769
25 Carceller DB, Sanz París A, Sánchez Oriz E, . TREATMENT OF SUBCLINICAL HYPERTHYROIDISM: EFFECT ON BODY COMPOSITION. Nutr Hosp. 2015;32(5):2331–2337.26545695
26 Chan D-CD, Tsou H-H, Yang R-S, . A pilot randomized controlled trial to improve geriatric frailty. BMC Geriatr. 2012;12(1):58–58.23009149
27 Chan T, de Lusignan S, Cooper A, Elliott M. Improving Osteoporosis Management in Primary Care: An Audit of the Impact of a Community Based Fracture Liaison Nurse. PLoS One. 2015;10(8):e0132146.26313924
28 Chan ACH, Adachi JD, Papaioannou A, Wong AKO. Investigating the Effects of Motion Streaks on pQCT-Derived Leg Muscle Density and Its Association With Fractures. J Clin Densitom. 2018;21(1):130–139.28065423
29 Chang SF, Hong CM, Yang RS. Global computer-assisted appraisal of osteoporosis risk in Asian women: an innovative study. J Clin Nurs. 2011;20(9–10):1357–1364.21492281
30 Chang IC, Jong-Shiuan Y, Nai-Wen T, . Association between renin-angiotensin-aldosterone system blockade and future osteoporotic fracture risk in hypertensive population: A population-based cohort study in Taiwan. Medicine. 2017;96(46):1–8.
31 Chen Y, Liu X, Cai D. Evaluation on effect of health education for middle-aged and senile patients with osteoporosis in community. Chinese Nursing Research. 2006;20(3A):650–652.
32 Chen JS, Sambrook PN, Simpson JM, . Risk factors for hip fracture among institutionalised older people. Age Ageing. 2009;38(4):429–434.19406974
33 Chitre MM, Hayes W. 3-year results of a member and physician intervention to reduce risk associated with glucocorticoid-induced osteoporosis in a health plan. J Manag Care Pharm. 2008;14(3):281–290.18439050
34 Ciaschini PM, Straus SE, Dolovich LR, . Community based intervention to optimize osteoporosis management: randomized controlled trial. BMC Geriatr. 2010;10:60.20799973
35 Clark EM, Gould V, Morrison L, Ades AE, Dieppe P, Tobias JH. Randomized controlled trial of a primary care-based screening program to identify older women with prevalent osteoporotic vertebral fractures: Cohort for Skeletal Health in Bristol and Avon (COSHIBA). J Bone Miner Res. 2012;27(3):664–671.22113935
36 Collinge C, LeBus G, Gardner MJ, Gehrig L. Osteoporosis in orthopaedic trauma patients: a diagnosis and treatment protocol. J Orthop Trauma. 2008;22(8):541–547; discussion 548-549.18758285
37 Compston JE, Wyman A, FitzGerald G, . Increase in Fracture Risk Following Unintentional Weight Loss in Postmenopausal Women: The Global Longitudinal Study of Osteoporosis in Women. J Bone Miner Res. 2016;31(7):1466–1472.26861139
38 Cooper C, Westlake S, Harvey N, Javaid K, Dennison E, Hanson M. Review: developmental origins of osteoporotic fracture. Osteoporos Int. 2006;17(3):337–347.16331359
39 Cox H, Puffer S, Morton V, . Educating nursing home staff on fracture prevention: a cluster randomised trial. Age Ageing. 2008;37(2):167–172.18083724
40 Cram P, Schlechte J, Christensen A. A randomized trial to assess the impact of direct reporting of DXA scan results to patients on quality of osteoporosis care. J Clin Densitom. 2006;9(4):393–398.17097523
41 Cram P, Wolinsky FD, Lou Y, . Patient-activation and guideline-concordant pharmacological treatment after bone density testing: the PAADRN randomized controlled trial. Osteoporos Int. 2016;27(12):3513–3524.27363400
42 Crockett JA, Taylor SJ, McLeod LJ. Patient responses to an integrated service, initiated by community pharmacists, for the prevention of osteoporosis. Int J Pharm Pract. 2008;16(2):65–72.
43 Curry LC, Hogstel MO, Davis GC, Frable PJ. Population-based osteoporosis education for older women. Public Health Nurs. 2002;19(6):460–469.12406180
44 D’Alesio V, Salvig BE, Fourakre TN. Evaluation of osteoporosis risk assessment in veterans receiving androgen-deprivation therapy. Consult Pharm. 2011;26(1):43–47.21224198
45 Danila MI, Outman RC, Rahn EJ, . A multi-modal intervention for Activating Patients at Risk for Osteoporosis (APROPOS): Rationale, design, and uptake of online study intervention material. Contemp Clin Trials Commun. 2016;4:14–24.27453960
46 Davis P, Kvern B, Donen N, Andrews E, Nixon O. Evaluation of a problem-based learning workshop using pre- and post-test objective structured clinical examinations and standardized patients. J Contin Educ Health Prof. 2000;20(3):164–170.11232252
47 Daya N, Voskertchian A, Schneider ALC, . Kidney Function and Fracture Risk: The Atherosclerosis Risk in Communities (ARIC) Study. Am J Kidney Dis. 2016;67(2):218–226.26250781
48 Demark-Wahnefried W, Clipp EC, Lipkus IM, . Main outcomes of the FRESH START trial: a sequentially tailored, diet and exercise mailed print intervention among breast and prostate cancer survivors. J Clin Oncol. 2007;25(19):2709–2718.17602076
49 Dewing K, Belza B, Zierler B, Lacroix AZ. Health maintenance module improves BMD testing. Nurse Pract. 2013;38(4):37–41.23507912
50 Dobson R, Leddy SG, Gangadharan S, Giovannoni G. Assessing fracture risk in people with MS: a service development study comparing three fracture risk scoring systems. BMJ Open. 2013;3(3).
51 Dore N, Kennedy C, Fisher P, Dolovich L, Farrauto L, Papaioannou A. Improving care after hip fracture: the fracture? Think osteoporosis (FTOP) program. BMC Geriatr. 2013;13:130.24314319
52 Dugard MN, Jones TJ, Davie MW. Uptake of treatment for osteoporosis and compliance after bone density measurement in the community. J Epidemiol Community Health. 2010;64(6):518–522.19679704
53 Edmonds SW, Cram P, Lou Y, . Effects of a DXA result letter on satisfaction, quality of life, and osteoporosis knowledge: a randomized controlled trial. BMC Musculoskelet Disord. 2016;17(1):369.27562713
54 Edwards BJ, Koval K, Bunta AD, . Addressing secondary prevention of osteoporosis in fracture care: Follow-up to “own the bone”. Journal of Bone and Joint Surgery - Series A. 2011;93(15):e87.81–e87.87.
55 Elias MN, Burden AM, Cadarette SM. The impact of pharmacist interventions on osteoporosis management: a systematic review. Osteoporos Int. 2011;22(10):2587–2596.21720894
56 Elliott ME, Meek PD, Kanous NL, . Osteoporosis screening by community pharmacists: use of National Osteoporosis Foundation resources. J Am Pharm Assoc (Wash). 2002;42(1):101–110; quiz 110-101.11833500
57 Elliott ME, Meek PD, Kanous NL, . Pharmacy-based bone mass measurement to assess osteoporosis risk. Ann Pharmacother. 2002;36(4):571–577.11918501
58 Elliott M. Taking control of osteoporosis to cut down on risk of fracture. Nurs Older People. 2011;23(3):30–35.21561030
59 Eyigör S, Karapolat H, Durmaz B. Medical students’ knowledge of osteoporosis in Ege University Faculty of Medicine. Romatizma. 2008;23(3):77–81.
60 Feskanich D, Willett WC, Stampfer MJ, Colditz GA. A prospective study of thiazide use and fractures in women. Osteoporos Int. 1997;7(1):79–84.9102069
61 Fournier A, Mesrine S, Gelot A, . Use of bisphosphonates and risk of breast cancer in a French cohort of postmenopausal women. J Clin Oncol. 2017;35(28):3230–3239.28708471
62 Freedman BA, Potter BK, Nesti LJ, Cho T, Kuklo TR. Missed opportunities in patients with osteoporosis and distal radius fractures. Clin Orthop Relat Res. 2007;454:202–206.17006362
63 Gadkaree SK, Sun DQ, Huang J, Varadhan R, Agrawal Y. Comparison of simple versus performance-based fall prediction models: Data from the national health and aging trends study. Gerontology and Geriatric Medicine. 2015;2015.
64 Ganda K, Schaffer A, Pearson S, Seibel MJ. Compliance and persistence to oral bisphosphonate therapy following initiation within a secondary fracture prevention program: a randomised controlled trial of specialist vs. non-specialist management. Osteoporos Int. 2014;25(4):1345–1355.24445732
65 Gardner MJ, Flik KR, Mooar P, . Improvement in the undertreatment of osteoporosis following hip fracture. Journal of Bone & Joint Surgery, American Volume. 2002;84(8):1342–1348.12177263
66 Gardner MJ, Brophy RH, Demetrakopoulos D, . Interventions to improve osteoporosis treatment following hip fracture. A prospective, randomized trial. J Bone Joint Surg Am. 2005;87(1):3–7.15634808
67 Genuis SJ, Bouchard TP. Combination of Micronutrients for Bone (COMB) Study: bone density after micronutrient intervention. J Environ Public Health. 2012;2012:354151.22291722
68 Giannini S, Chiarello E, Mazzotti A, Tedesco G, Faldini C. Surgical prevention of femoral neck fractures in elderly osteoporotic patients: a randomised controlled study on the prevention nail system device. Hip Int. 2018;28:78–83.30755119
69 Giusti A, Barone A, Razzano M, . Persistence with calcium and vitamin D in elderly patients after hip fracture. J Bone Miner Metab. 2009;27(1):95–100.19018453
70 Glidewell L, West R, Hackett JE, Carder P, Doran T, Foy R. Does a local financial incentive scheme reduce inequalities in the delivery of clinical care in a socially deprived community? A longitudinal data analysis. BMC Fam Pract. 2015;16:61.25971774
71 Goldshtein I, Shamai-Lubovitz O, Guindy M, . Development and efficacy of a computerized decision support system for osteoporosis management in the community. Arch Osteoporos. 2020;15(1):27.32103347
72 Gomez F, Curcio CL, Brennan-Olsen SL, . Effects of the falls and fractures clinic as an integrated multidisciplinary model of care in Australia: a pre-post study. BMJ Open. 2019;9(7):e027013.
73 Gonnelli S, Cepollaro C, Gennari L, . Quantitative ultrasound and dual-energy X-ray absorptiometry in the prediction of fragility fracture in men. Osteoporos Int. 2005;16(8):963–968.15599495
74 Goode SC, Beshears JL, Goode RD, Wright TF, King A, Crist BD. Putting the Brakes on Breaks: Osteoporosis Screening and Fracture Prevention. Geriatr Orthop Surg Rehabil. 2017;8(4):238–243.29318086
75 Gossec L, Soubrier M, Foissac F, . Screening for and management of comorbidities after a nurse-led program: results of a 3-year longitudinal study in 769 established rheumatoid arthritis patients. RMD Open. 2019;5(2):e000914.31275607
76 Greene D, Dell RM. Outcomes of an osteoporosis disease-management program managed by nurse practitioners. J Am Acad Nurse Pract. 2010;22(6):326–329.20536631
77 Greenspan SL, Wyman A, Hooven FH, . Predictors of treatment with osteoporosis medications after recent fragility fractures in a multinational cohort of postmenopausal women. J Am Geriatr Soc. 2012;60(3):455–461.22316070
78 Gupta MJ, Shah S, Peterson S, Baim S. Rush Fracture Liaison Service for capturing “missed opportunities” to treat osteoporosis in patients with fragility fractures. Osteoporos Int. 2018;29(8):1861–1874.29869038
79 Hall LN, Shrader SP, Ragucci KR. Evaluation of compliance with osteoporosis treatment guidelines after initiation of a pharmacist-run osteoporosis service at a family medicine clinic. Ann Pharmacother. 2009;43(11):1781–1786.19826096
80 Hansen KE, Rosenblatt ER, Gjerde CL, Crowe ME. Can an online osteoporosis lecture increase physician knowledge and improve patient care? J Clin Densitom. 2007;10(1):10–20.17289521
81 Hansma AHG, Emmelot-Vonk MH, Verhaar HJJ. Reduction in falling after a falls-assessment. Arch Gerontol Geriatr. 2010;50(1):73–76.19243845
82 Hawker G, Ridout R, Ricupero M, Jaglal S, Bogoch E. The impact of a simple fracture clinic intervention in improving the diagnosis and treatment of osteoporosis in fragility fracture patients. Osteoporos Int. 2003;14(2):171–178.12730739
83 Hawley S, Javaid MK, Prieto-Alhambra D, . Clinical effectiveness of orthogeriatric and fracture liaison service models of care for hip fracture patients: population-based longitudinal study. Age Ageing. 2016;45(2):236–242.26802076
84 Heilmann RM, Friesleben CR, Billups SJ. Impact of a pharmacist-directed intervention in postmenopausal women after fracture. Am J Health Syst Pharm. 2012;69(6):504–509.22382482
85 Hess BJ, Johnston MM, Iobst WF, Lipner RS. Practice-based learning can improve osteoporosis care. J Am Geriatr Soc. 2013;61(10):1651–1660.24117284
86 Ho C, Cranney A, Campbell A. Measuring the impact of pharmacist intervention: Results of patient education about osteoporosis after fragility fracture. Can J Hosp Pharm. 2006;59(4):184–193.
87 Hodsman AB, Platt N, Stitt L, . Evaluation of an Osteoporosis Self-Referral Program to Enhance Management Outcomes. J Clin Densitom. 2004;7(1):77–83.14742891
88 Hofflich HL, Oh DK, Choe CH, . Using a Triggered Endocrinology Service Consultation to Improve the Evaluation, Management, and Follow-Up of Osteoporosis in Hip-Fracture Patients. Joint Commission Journal on Quality & Patient Safety. 2014;40(5):228–234.24919254
89 Hudson B, Toop L, Mangin D, Pearson J. Risk communication methods in hip fracture prevention: a randomised trial in primary care. Br J Gen Pract. 2011;61(589):e469–476.21801539
90 Huntjens KM, van Geel TC, Geusens PP, . Impact of guideline implementation by a fracture nurse on subsequent fractures and mortality in patients presenting with non-vertebral fractures. Injury. 2011;42 Suppl 4:S39–43.21939802
91 Huntjens KM, van Geel TA, Blonk MC, . Implementation of osteoporosis guidelines: a survey of five large fracture liaison services in the Netherlands. Osteoporos Int. 2011;22(7):2129–2135.21052640
92 Iki M, Fujita Y, Tamaki J, . Design and baseline characteristics of a prospective cohort study for determinants of osteoporotic fracture in community-dwelling elderly Japanese men: the Fujiwara-kyo osteoporosis risk in men (FORMEN) study. BMC Musculoskelet Disord. 2009;10:165.20030855
93 Inderjeeth CA, Glennon DA, Poland KE, . A multimodal intervention to improve fragility fracture management in patients presenting to emergency departments. Med J Aust. 2010;193(3):149–153.20678042
94 Ioannidis G, Thabane L, Gafni A, . Optimizing care in osteoporosis: the Canadian quality circle project. BMC Musculoskelet Disord. 2008;9:130.18828906
95 Irwin AN, Heilmann RM, Gerrity TM, Kroner BA, Olson KL. Use of a pharmacy technician to facilitate postfracture care provided by clinical pharmacy specialists. Am J Health Syst Pharm. 2014;71(23):2054–2059.25404597
96 Izuora KE, Alazraki N, Byrd-Sellers J, Tangpricha V, Nanes MS. Fracture assessment tool risk scores in bone density reports do not change physician prescribing behavior for osteoporosis. Am J Med Sci. 2011;342(1):5–8.21412137
97 Jaglal SB, Hawker G, Bansod V, . A demonstration project of a multi-component educational intervention to improve integrated post-fracture osteoporosis care in five rural communities in Ontario, Canada. Osteoporos Int. 2009;20(2):265–274.18521649
98 Jensen CL, Petersen MM, Schrøder HM, . Bone mineral density changes of the proximal tibia after revision total knee arthroplasty. A randomised study with the use of porous tantalum metaphyseal cones. Int Orthop. 2012;36(9):1857–1863.22733440
99 Jiang X, Good LE, Spinka R, Schnatz PF. Osteoporosis screening in postmenopausal women aged 50-64 years: BMI alone compared with current screening tools. Maturitas. 2016;83:59–64.26471931
100 Jones G. Early life nutrition and bone development in children. Nestle Nutr Workshop Ser Pediatr Program. 2011;68:227–233; discussion 233-226.
101 Joy MS, Neyhart CD, Dooley MA. A multidisciplinary renal clinic for corticosteroid-induced bone disease. Pharmacotherapy. 2000;20(2):206–216.10678299
102 Kastner M, Lottridge D, Marquez C, Newton D, Straus SE. Usability evaluation of a clinical decision support tool for osteoporosis disease management. Implement Sci. 2010;5:96.21143978
103 Kennedy CC, Ioannidis G, Thabane L, . Successful knowledge translation intervention in long-term care: final results from the vitamin D and osteoporosis study (ViDOS) pilot cluster randomized controlled trial. Trials. 2015;16:214.25962885
104 Kesman RL, Rahman AS, Lin EY, Barnitt EA, Chaudhry R. Population informatics-based system to improve osteoporosis screening in women in a primary care practice. J Am Med Inform Assoc. 2010;17(2):212–216.20190066
105 Kim JY, Yoo JH, Kim JW, . Pop-up messages in order communication systems can increase awareness of osteoporosis among physicians and improve osteoporosis treatment. J Eval Clin Pract. 2016;22(6):887–891.27151774
106 Kimber CM, Grimmer-Somers KA. Multifaceted guideline implementation strategies improve early identification and management of osteoporosis. Aust Health Rev. 2009;33(3):423–433.20128758
107 Kirk JK, Nichols M, Spangler JG. Use of a peripheral dexa measurement for osteoporosis screening. Fam Med. 2002;34(3):201–205.11922536
108 Kruger MC, Todd JM, Schollum LM, Kuhn-Sherlock B, McLean DW, Wylie K. Bone health comparison in seven Asian countries using calcaneal ultrasound. BMC Musculoskelet Disord. 2013;14:81.23497143
109 Kuczynski HJ, Rogers ML. A retrospective study: osteoporosis and hormone replacement therapy. Curationis. 1989;12(1/2):9–12.2676219
110 Lakatos P, Toth E, Szekeres L, . Comparative statistical analysis of osteoporosis treatment based on Hungarian claims data and interpretation of the results in respect to cost-effectiveness. Osteoporos Int. 2014;25(8):2077–2087.24819455
111 Laliberte MC, Perreault S, Dragomir A, . Impact of a primary care physician workshop on osteoporosis medical practices. Osteoporos Int. 2010;21(9):1471–1485.19937428
112 Laslett LL, Whitham JN, Gibb C, Gill TK, Pink JA, McNeil JD. Improving diagnosis and treatment of osteoporosis: Evaluation of a clinical pathway for low trauma fractures. Archives of Osteoporosis. 2007;2(1–2):1–6.
113 Laufer M, Keller T, Gershman V, Ferman Z, Sarid M, Leibovitch I. [InoPro trial: collaboration between urologists and primary care physicians in the treatment of osteoporosis in prostate cancer patients]. Harefuah. 2014;153(3–4):151–154, 240.24791553
114 Law AV, Shapiro K. Impact of a community pharmacist-directed clinic in improving screening and awareness of osteoporosis. J Eval Clin Pract. 2005;11(3):247–255.15869555
115 Lee YH, Lim YW, Ling PS, Tan YY, Cheong M, Lam KS. Inadequate dietary calcium intake in elderly patients with hip fractures. Singapore Med J. 2007;48(12):1117–1121.18043839
116 Lee RH, Pearson M, Lyles KW, Jenkins PW, Colon-Emeric C. Geographic scope and accessibility of a centralized, electronic consult program for patients with recent fracture. Rural Remote Health. 2016;16(1):3440.26745338
117 Lee KS, Jung SK, Ryu JJ, Shin SW, Choi J. Evaluation of Transfer Learning with Deep Convolutional Neural Networks for Screening Osteoporosis in Dental Panoramic Radiographs. J Clin Med. 2020;9(2).
118 Leeangkoonsathian E, Boonyanuruk P, Pongchaiyakul C, Panichkul S. Validate of clinical risk index for osteoporosis in Thai women at Phramongkutklao Hospital. J Med Assoc Thai. 2012;95(4):487–492.22612000
119 Leslie WD, Lix LM. Effects of FRAX((R)) model calibration on intervention rates: a simulation study. J Clin Densitom. 2011;14(3):272–278.21723769
120 Leslie WD, Morin S, Lix LM. A Before-and-After Study of Fracture Risk Reporting and Osteoporosis Treatment Initiation. Ann Intern Med. 2010;153(9):580–586.21041577
121 Lin JW, Chu PL, Liou JM, Hwang JJ. Applying a multiple screening program aided by a guideline-driven computerized decision support system - a pilot experience in Yun-Lin, Taiwan. J Formos Med Assoc. 2007;106(1):58–68.17282972
122 Long MD, Thiny MT, Sandler RS, Gangarosa LM. Bone health in a tertiary-care gastroenterology and hepatology population. Dig Dis Sci. 2010;55(8):2263–2269.20127169
123 Lord SR, Ward JA, Williams P, Zivanovic E. The effects of a community exercise program on fracture risk factors in older women. Osteoporos Int. 1996;6(5):361–367.8931030
124 Lovric M, Ribom-Bornefalk E. [More investigated for osteoporosis after the introduction of a fracture liaison service]. Lakartidningen. 2016;113.
125 Lufkin EG, Whitaker MD, Nickelsen T, . Treatment of established postmenopausal osteoporosis with raloxifene: a randomized trial. J Bone Miner Res. 1998;13(11):1747–1754.9797484
126 Lukert B, Satram-Hoang S, Wade S, Anthony M, Gao G, Downs R. Physician differences in managing postmenopausal osteoporosis: results from the POSSIBLE US treatment registry study. Drugs Aging. 2011;28(9):713–727.21913737
127 MacIntyre J, Drake P, Garland-Baird L, Loo J, Nisbet M, McClure C. Optimizing osteoporosis care in a rural primary health care center: Findings of a research study aimed to support seniors. Nurs Forum. 2019;54(4):611–618.31506955
128 MacLaughlin EJ, MacLaughlin AA, Snella KA, Winston TS, Fike DS, Raehl CR. Osteoporosis screening and education in community pharmacies using a team approach. Pharmacotherapy. 2005;25(3):379–386.15843285
129 Magill-Lewis J. How to set up a program in osteoporosis screening. Drug Topics. 2006;150(6).
130 Majumdar SR, Rowe BH, Folk D, . A controlled trial to increase detection and treatment of osteoporosis in older patients with a wrist fracture. Ann Intern Med. 2004;141(5):366–373.15353428
131 Majumdar SR, Beaupre LA, Harley CH, . Use of a case manager to improve osteoporosis treatment after hip fracture: results of a randomized controlled trial. Arch Intern Med. 2007;167(19):2110–2115.17954806
132 Majumdar SR, Johnson JA, McAlister FA, . Multifaceted intervention to improve diagnosis and treatment of osteoporosis in patients with recent wrist fracture: a randomized controlled trial. CMAJ. 2008;178(5):569–575.18299546
133 Majumdar SR, Lier DA, Rowe BH, . Cost-effectiveness of a multifaceted intervention to improve quality of osteoporosis care after wrist fracture. Osteoporos Int. 2010:1–10.
134 Majumdar SR, Johnson JA, Bellerose D, . Nurse case-manager vs multifaceted intervention to improve quality of osteoporosis care after wrist fracture: randomized controlled pilot study. Osteoporos Int. 2011;22(1):223–230.20358359
135 Malgo F, Appelman-Dijkstra NM, Termaat MF, . High prevalence of secondary factors for bone fragility in patients with a recent fracture independently of BMD. Arch Osteoporos. 2016;11:12.26906974
136 Mastaglia SR, Bagur A, Goldstein G, Parisi MS, Oliveri B. Results of a detection campaign in a population at risk of developing osteoporosis and fractures. Revista Espanola de Enfermedades Metabolicas Oseas. 2005;14(4):61–66.
137 Merchant R, Udani A, Puri V, . Evaluation of osteopathy in thalassemia by bone mineral densitometry and biochemical indices. Indian J Pediatr. 2010;77(9):987–991.20737251
138 Merz CNB. Hormone therapy and cardiovascular risk: Why the new focus on perimenopausal women? Advanced Studies in Medicine. 2006;6(6):267–274.
139 Mosekilde L, Hermann AP, Beck-Nielsen H, Charles P, Nielsen SP, Sorensen OH. The Danish Osteoporosis Prevention Study (DOPS): project design and inclusion of 2000 normal perimenopausal women. Maturitas. 1999;31(3):207–219.10340280
140 Nakamoto T, Taguchi A, Ohtsuka M, . A computer-aided diagnosis system to screen for osteoporosis using dental panoramic radiographs. Dentomaxillofac Radiol. 2008;37(5):274–281.18606749
141 Naunton M, Peterson GM, Jones G, Griffin GM, Bleasel MD. Multifaceted educational program increases prescribing of preventive medication for corticosteroid induced osteoporosis. J Rheumatol. 2004;31(3):550–556.14994404
142 Navarro RA, Greene DF, Burchette R, Funahashi T, Dell R. Minimizing disparities in osteoporosis care of minorities with an electronic medical record care plan. Clin Orthop Relat Res. 2011;469(7):1931–1935.21424836
143 Nelson SD, Nelson RE, Cannon GW, . Cost-effectiveness of training rural providers to identify and treat patients at risk for fragility fractures. Osteoporos Int. 2014;25(12):2701–2707.25037601
144 Nendaz M. The efficacy of a treatment: Absolute and relative risk, number of patients to be treated. Schweizerische Rundschau fur Medizin - Praxis. 2005;94(14):553–554.
145 Newman ED, Hanus P. Improved bone health behavior using community pharmacists as educators: The Geisinger Health System Community Pharmacist Osteoporosis Education Program. Disease Management and Health Outcomes. 2001;9(6):329–335.
146 O’Brien LK, Armstrong AD, Hassenbein SE, Fox EJ. Evaluation of Patients’ Response Toward Osteoporosis Letter Intervention Versus Phone Call Plus Letter Intervention. Geriatr Orthop Surg Rehabil. 2015;6(4):246–250.26623157
147 Oh EG, Lee JE, Yoo JY. A systematic review of the effectiveness of lifestyle interventions for improving bone health in women at high risk of osteoporosis. JBI Libr Syst Rev. 2012;10(30):1738–1784.27820225
148 Olegario R, Park J, Kjell J. Clinical pharmacists boost success of osteoporosis outreach effort. Drug Benefit Trends. 2008;20(10):391–400.
149 O’Neil C, Berdine H. Experiential education at a university-based wellness center. Am J Pharm Educ. 2007;71(3):49.17619649
150 O’Neill TW, Marsden D, Matthis C, Raspe H, Silman AJ. Survey response rates: national and regional differences in a European multicentre study of vertebral osteoporosis. J Epidemiol Community Health. 1995;49(1):87–93.7707013
151 O’Neill TW, Marsden D, Silman AJ. Differences in the characteristics of responders and non-responders in a prevalence survey of vertebral osteoporosis. European Vertebral Osteoporosis Study Group. Osteoporos Int. 1995;5(5):327–334.8800782
152 Orimo H, Sato M, Kimura S, . Understanding the factors associated with initiation and adherence of osteoporosis medication in Japan: An analysis of patient perceptions. Osteoporosis and Sarcopenia. 2017;3(4):174–184.30775527
153 Parri S, Cianferotti L, Marcucci G, . The T.A.R.Ge.T. project: a regional program to reduce hip fracture in elderly patients. Main results of retrospective phase. Clin Cases Miner Bone Metab. 2015;12(1):34–42.26136794
154 Patel VP, Mathew R, Raptis D, Christofi T, Youngman J. Overcoming barriers to secondary prevention in hip fracture patients: An electronic referral and management system for osteoporosis. Injury. 2010;41(12):1249–1255.20538276
155 Penning-van Beest FJA, Goettsch WG, Erkens JA, Herings RMC. Determinants of persistence with bisphosphonates: a study in women with postmenopausal osteoporosis. Clin Ther. 2006;28(2):236–242.16678644
156 Peris P, Guanabens N, Monegal A, . Aetiology and presenting symptoms in male osteoporosis. Br J Rheumatol. 1995;34(10):936–941.7582699
157 Peters S, Singla D, Raney E. Impact of pharmacist-provided osteoporosis education and screening in the workplace. J Am Pharm Assoc (2003). 2006;46(2):216–218.16602232
158 Pezzotto SM, Morosano ME, Chapo G, Menoyo I, Bocanera R, Masoni AM. Detection of wedge fractures in the dorsal spine of asymptomatic menopausal women using two morphometric criteria. Prevalence rates. Rev Med Rosario. 2010;76(1):8–16.
159 Pfimlin A, Gournay A, Delabrière I, . Secondary prevention of osteoporotic fractures: evaluation of the Lille University Hospital’s Fracture Liaison Service between January 2016 and January 2018. Osteoporos Int. 2019.
160 Pluijm SM, Graafmans WC, Bouter LM, Lips P. Ultrasound measurements for the prediction of osteoporotic fractures in elderly people. Osteoporos Int. 1999;9(6):550–556.10624464
161 Polinski JM, Brookhart MA, Katz JN, . Educational outreach (academic detailing) regarding osteoporosis in primary care. Pharmacoepidemiol Drug Saf. 2005;14(12):843–850.15918162
162 Prihar BJ, Katz S. Patient education as a tool to increase screening for osteoporosis. J Am Geriatr Soc. 2008;56(5):961–962.18454765
163 Puisto V, Heliovaara M, Impivaara O, . Severity of vertebral fracture and risk of hip fracture: a nested case-control study. Osteoporos Int. 2011;22(1):63–68.20195843
164 Radford LT, Bolland MJ, Mason B, . The Auckland calcium study: 5-year post-trial follow-up. Osteoporos Int. 2014;25(1):297–304.24114400
165 Rapp K, Kampe K, Roigk P, . The osteoporotic fracture prevention program in rural areas (OFRA): a protocol for a cluster-randomized health care fund driven intervention in a routine health care setting. BMC Musculoskelet Disord. 2016;17(1):458.27821102
166 Ravn P. Bisphosphonates for prevention of postmenopausal osteoporosis. Dan Med Bull. 2002;49(1):1–18.11894721
167 Rencken ML, Murano R, Drinkwater BL, Chesnut CH, 3rd. In vitro comparability of dual energy X-ray absorptiometry (DEXA) bone densitometers. Calcif Tissue Int. 1991;48(4):245–248.2059876
168 Reuben DB, Gazarian P, Alexander N, . The Strategies to Reduce Injuries and Develop Confidence in Elders Intervention: Falls Risk Factor Assessment and Management, Patient Engagement, and Nurse Co-management. J Am Geriatr Soc. 2017;65(12):2733–2739.29044479
169 Rucker D, Rowe BH, Johnson JA, . Educational intervention to reduce falls and fear of falling in patients after fragility fracture: results of a controlled pilot study. Prev Med. 2006;42(4):316–319.16488469
170 Ryder KM, Bush A, Womack C, Pitts W. Poor health, but not fracture and fall risk, is associated with nonattendance at bone mineral density screening. South Med J. 2012;105(7):325–328.22766656
171 Saadi H, Litaker D, Mills W, Kippes C, Richmond B, Licata A. Practice variation in the diagnosis and treatment of osteoporosis: a case for more effective physician education in primary care. J Womens Health Gend Based Med. 1999;8(6):767–771.10495258
172 Şahin E, Dilek B, Baydar M, Kösehasanoǧullari M, Uçku R, Öncel S. Awareness of osteoporosis and its related factors after distal radius fractures in patients aged 45 years and older. Turkiye Fiziksel Tip ve Rehabilitasyon Dergisi. 2013;59(1):52–56.
173 Sale JE, Beaton DE, Elliot-Gibson VI, Bogoch ER, Ingram J. A postfracture initiative to improve osteoporosis management in a community hospital in ontario. J Bone Joint Surg Am. 2010;92(10):1973–1980.20720140
174 Salovaara K, Tuppurainen M, Karkkainen M, . Effect of vitamin D(3) and calcium on fracture risk in 65- to 71-year-old women: a population-based 3-year randomized, controlled trial--the OSTPRE-FPS. J Bone Miner Res. 2010;25(7):1487–1495.20200964
175 Salvig BE, Gulum AH, Walters SA, . Pharmacist Screening for Risk of Osteoporosis in Elderly Veterans. Consult Pharm. 2016;31(8):440–449.27535079
176 Schmajuk G, Yelin E, Chakravarty E, Nelson LM, Panopolis P, Yazdany J. Osteoporosis screening, prevention, and treatment in systemic lupus erythematosus: application of the systemic lupus erythematosus quality indicators. Arthritis Care Res (Hoboken). 2010;62(7):993–1001.20589692
177 Schoon Y, Hoogsteen-Ossewaarde ME, Scheffer AC, Van Rooij FJ, Rikkert MG, De Rooij SE. Comparison of different strategies of referral to a fall clinic: how to achieve an optimal casemix? J Nutr Health Aging. 2011;15(2):140–145.21365168
178 Schousboe JT, DeBold RC, Kuno LS, Weiss TW, Chen YT, Abbott ITA. Education and phone follow-up in postmenopausal women at risk for osteoporosis: Effects on calcium intake, exercise frequency, and medication use. Disease Management and Health Outcomes. 2005;13(6):395–404.
179 Schousboe JT, Ensrud KE, Nyman JA, Melton ILJ, Kane RL. Universal bone densitometry screening combined with alendronate therapy for those diagnosed with osteoporosis is highly cost-effective for elderly women. J Am Geriatr Soc. 2005;53(10):1697–1704.16181168
180 Seuffert P, Sagebien CA, McDonnell M, O’Hara DA. Evaluation of osteoporosis risk and initiation of a nurse practitioner intervention program in an orthopedic practice. Arch Osteoporos. 2016;11:10.26847628
181 Sheffet AM, Ridlen S, Louria DB. Baseline behavioral assessment for the New Jersey Health Wellness Promotion Act. Am J Health Promot. 2006;20(6):401–410.16871820
182 Shu AD, Stedman MR, Polinski JM, . Adherence to osteoporosis medications after patient and physician brief education: post hoc analysis of a randomized controlled trial. Am J Manag Care. 2009;15(7):417–424.19589009
183 Sikon AL, Thacker HL, Carey J, Deal C, Licata AA. Secondary osteoporosis: Are we recognizing it? J Womens Health. 2006;15(10):1174–1183.
184 Solomon DH, Brookhart MA, Polinski J, . Osteoporosis action: Design of the healthy bones project trial. Contemp Clin Trials. 2005;26(1):78–94.15837454
185 Solomon DH, Finkelstein JS, Polinski JM, . A randomized controlled trial of mailed osteoporosis education to older adults. Osteoporos Int. 2006;17(5):760–767.16432644
186 Stock JL, Waud CE, Coderre JA, . Clinical reporting to primary care physicians leads to increased use and understanding of bone densitometry and affects the management of osteoporosis. A randomized trial. Ann Intern Med. 1998;128(12 Pt 1):996–999.9625686
187 Summers KM, Brock TP. Impact of pharmacist-led community bone mineral density screenings. Ann Pharmacother. 2005;39(2):243–248.15613465
188 Talalaj M, Kapitan-Malinowska B, Debski K, Nowakowski R, Marcinowska-Suchowierska E, Witeska A. [Administration of 1 alpha-OH vitamin D3 and calcium prevents bone mass loss in patients with advanced prostatic carcinoma after orchidectomy treated with complete androgenic blockade]. Endokrynol Pol. 2005;56(3):225–232.16350714
189 Tamburino G, Fiore CE. Plasmatic markers of bone metabolism. Ann Ital Med Int. 1990;5(3 Pt 3):296–302.2081090
190 Torgerson DJ, Garton MJ, Donaldson C, Russell IT, Reid DM. Recruitment methods for screening programmes: trial of an improved method within a regional osteoporosis study. BMJ. 1993;307(6896):99.8343737
191 Tsang DS, Jones JM, Samadi O, . Healthy Bones Study: can a prescription coupled with education improve bone health for patients receiving androgen deprivation therapy?—a before/after study. Support Care Cancer. 2018;26(8):2861–2869.29532243
192 Unni S, Yao Y, Milne N, Gunning K, Curtis JR, LaFleur J. An evaluation of clinical risk factors for estimating fracture risk in postmenopausal osteoporosis using an electronic medical record database. Osteoporos Int. 2015;26(2):581–587.25288442
193 Uusi-Rasi K, Kannus P, Karinkanta S, . Study protocol for prevention of falls: a randomized controlled trial of effects of vitamin D and exercise on falls prevention. BMC Geriatr. 2012;12:12.22448872
194 van Boven JF, Stuurman-Bieze AG, Hiddink EG, Postma MJ, Vegter S. Medication monitoring and optimization: a targeted pharmacist program for effective and cost-effective improvement of chronic therapy adherence. J Manag Care Spec Pharm. 2014;20(8):786–792.25062071
195 van Helden S, Cauberg E, Geusens P, Winkes B, van der Weijden T, Brink P. The fracture and osteoporosis outpatient clinic: an effective strategy for improving implementation of an osteoporosis guideline. J Eval Clin Pract. 2007;13(5):801–805.17824875
196 Varacallo MA, Fox EJ, Paul EM, Hassenbein SE, Warlow PM. Patients’ response toward an automated orthopedic osteoporosis intervention program. Geriatr Orthop Surg Rehabil. 2013;4(3):89–98.24319621
197 Vogel T, Bitterling H, Dobler T, Bartl R, Pfeifer KJ, Mutschler W. [Contemporary diagnostics and therapy of osteoporosis]. Zentralbl Chir. 2006;131(5):401–406.17089289
198 Wang S, Lin S, Zhou Y, Wang Z. Social and behavior factors related to aged Chinese women with osteoporosis. Gynecol Endocrinol. 2008;24(10):538–545.19012095
199 Warriner AH, Curtis JR. Adherence to osteoporosis treatments: Room for improvement. Curr Opin Rheumatol. 2009;21(4):356–362.19412103
200 Warriner AH, Outman RC, Allison JJ, . An Internet-based Controlled Trial Aimed to Improve Osteoporosis Prevention among Chronic Glucocorticoid Users. J Rheumatol. 2015;42(8):1478–1483.26136484
201 Warshaw G. Risk management challenges in long-term care. Ann Longterm Care. 2013;21(2):8.
202 Werner P, Vered I. The diagnosis of osteoporsis: Attitudes and knowledge of Israeli physicians. Aging - Clinical and Experimental Research. 2002;14(1):52–59.12027154
203 Werner P, Olchovsky D, Erlich-Gelaki H, Vered I. First-degree relatives of persons suffering from osteoporosis: Beliefs, knowledge, and health-related behavior. Osteoporos Int. 2003;14(4):306–311.12730789
204 Wolinsky FD, Lou Y, Edmonds SW, . Activating Patients With a Tailored Bone Density Test Results Letter and Educational Brochure: the PAADRN Randomized Controlled Trial. J Clin Densitom. 2017;20(4):464–471.27647261
205 Woltman K, den Hoed PT. Osteoporosis in patients with a low-energy fracture: 3 years of screening in an osteoporosis outpatient clinic. J Trauma. 2010;69(1):169–173.20375916
206 Wong SY, Lau EM, Lau WW, Lynn HS. Is dietary counselling effective in increasing dietary calcium, protein and energy intake in patients with osteoporotic fractures? A randomized controlled clinical trial. J Hum Nutr Diet. 2004;17(4):359–364.15250845
207 Woo A, Hittell J, Beardsley C, Noh C, Stoukides CA, Kaul AF. An ongoing six-year innovative osteoporosis disease management program: challenges and success in an IPA physician group environment. Dis Manag. 2004;7(3):216–225.15669581
208 Wu F, Laslett LL, Wills K, Oldenburg B, Jones G, Winzenberg T. Effects of individualized bone density feedback and educational interventions on osteoporosis knowledge and self-efficacy: a 12-yr prospective study. J Clin Densitom. 2014;17(4):466–472.25220886
209 Wyshak G. Percent body fat, fractures and risk of osteoporosis in women. Journal of Nutrition, Health and Aging. 2010;14(6):428–432.
210 Yi X, Lu H, Tian F, . Recompression in new levels after percutaneous vertebroplasty and kyphoplasty compared with conservative treatment. Arch Orthop Trauma Surg. 2014;134(1):21–30.24287674
211 Yuksel N, Majumdar SR, Biggs C, Tsuyuki RT. Design of a randomized trial of a community pharmacist-initiated screening and intervention program for osteoporosis. Canadian Pharmacists Journal. 2006;139(2):50–51.
212 Zhang Y-P, Li X-M, Wang D-L, Guo X-Y, Guo X. Evaluation of educational program on osteoporosis awareness and prevention among nurse students in China. Nurs Health Sci. 2012;14(1):74–80.22303915
213 Zisblatt L, Kues JR, Davis N, Willis CE. The long-term impact of a performance improvement continuing medical education intervention on osteoporosis screening. J Contin Educ Health Prof. 2013;33(4):206–214.24347099
214 Zwart M, Azagra R, Encabo G, . Measuring health-related quality of life in men with osteoporosis or osteoporotic fracture. BMC Public Health. 2011;11:775.21981790