# APPENDIX D KQ 1 AND KQ 2 EXCLUDED STUDIES

Study | Exclusion Reason
| Population | Intervention | Outcomes | Comparator | Design | Setting | OECD
Abderhalden, 2017^1^ | X
Ackman, 2014^2^ | | | | X
Adami, 2003^3^ | | X
Adams, 2019^4^ | | X
Adler, 2003^5^ | | | | | | X
Aguirre, 2017^6^ | | | | X
Alajlouni, 2020^7^ | | X
Albaba, 2012^8^ | X
Albright, 2014^9^ | | X
Alcalde Vargas, 2012^10^ | | X
Allin, 2016^11^ | X
Almog, 2020^12^ | X
Amin , 2001^13^ | | | | | | | X
Andersen , 2015^14^ | | X
Arabi, 2005^15^ | | | | | | | X
Asirvatham, 2019^16^ | X
Aspray, 2006^17^ | X
Aubry-Rozier, 2013^18^ | X
Aynardi , 2013^19^ | | | | | | | X
Ayres, 2012^20^ | X
Barbour, 2010^21^ | | X
Barrett-Connor, 2012^22^ | | X
Bass, 2007^23^ | | | | X
Bauer, 2009^24^ | | X
Beaton, 2017^25^ | X
Beattie, 2014^26^ | X
Beattie, 2015^27^ | X
Beaudoin, 2019^28^ | | | | | X
Beck, 1996^29^ | | X
Bedimo, 2012^30^ | X
Berry , 2007^31^ | | | | | | | X
Bethel, 2016^32^ | X
Bethel, 2016^33^ | | X
Bethel, 2016^34^ | | X
Bhat, 2017^35^ | | | | | | | X
Bisson, 2019^36^ | X
Blanchard, 2019^37^ | X
Blomeier , 2005^38^ | | | | X
Bolton, 2017^39^ | X
Borade, 2016^40^ | X
Bours, 2016^41^ | X
Bow, 2011^42^ | | | | | | | X
Brinton, 2019^43^ | | | | | X
Broussard , 2004^44^ | | X
Broussard , 2008^45^ | | X
Calmy, 2009^46^ | | | | | | X
Caplan, 2011^47^ | | X
Carnevale, 2014^48^ | | | | X
Caughey, 2010^49^ | | X
Cervinka, 2017^50^ | | | | | X
Chalhoub, 2015^51^ | | X
Chalhoub, 2016^52^ | | | | X
Chan, 2012^53^ | | X
Chang , 2016^54^ | | | | | | | X
Chang, 2016^55^ | | | | | | | X
Chao, 2020^56^ | | | | | | | X
Chen, 2014^57^ | | X
Chen, 2015^58^ | | | | | | | X
Chen, 2016^59^ | | | | | | | X
Cheng, 2010^60^ | X
Chuang, 2019^61^ | | | | | | | X
Cirnigliaro, 2019^62^ | X
Clarke, 2014^63^ | | | | | X
Colon-Emeric, 2002^64^ | X
Colon-Emeric, 2018^65^ | | X
Couraud, 2017^66^ | X
Couris, 2012^67^ | | X
Cronholm, 2019^68^ | | X
De Laet, 1998^69^ | | X
Dell, 2009^70^ | X
Derkatch, 2019^71^ | X
Dicken, 2016^72^ | X
Duncan, 2014^73^ | | | | X
E, 2020^74^ | | X
Edwards, 2013^75^ | | X
El Maghraoui , 2008^76^ | | | | | | | X
El-Gabalawy, 2018^77^ | X
Elliott, 2000^78^ | | X
Ensrud, 2014^79^ | X
Faulkner, 2009^80^ | | X
Fink, 2014^81^ | | X
Forgetta, 2020^82^ | | | | X
Fransiska, 2012^83^ | | | | | | | X
Fraser, 2011^84^ | | | | | X
Frost, 2009^85^ | | X
Fu, 2021^86^ | | | | | X
Funkhouser, 2002^87^ | X
Gadam, 2013^88^ | X
Geusens , 2012^89^ | | | | | | | X
Giangregorio, 2012^90^ | X
Gielen, 2014^91^ | | X
Gill, 2015^92^ | | X
Gimigliano, 2015^93^ | X
Gómez Alonso, 2000^94^ | | X
Gotthardt, 2017^95^ | | X
Gould, 2013^96^ | | X
Gourlay, 2016^97^ | | X
Greenwald, 2003^98^ | X
Gruber, 2013^99^ | | X
Gupta, 2019^100^ | X
Hanusch, 2017^101^ | | X
Harvey, 2018^102^ | | X
Harvey, 2018^103^ | | | | | | | X
Hayashi, 2015^104^ | | | X
Hoff, 2018^105^ | | X
Ho-Le, 2017^106^ | | X
Holloway, 2015^107^ | | | X
Holloway, 2018^108^ | | X
Holloway-Kew, 2021^109^ | | | | X
Hsu, 2020^110^ | | | | | | | X
Huang, 2017^111^ | | | | | | | X
Jain , 2017^112^ | | X
Jamal, 2014^113^ | X
Jefferies, 2016^114^ | | X
Jehle, 2013^115^ | | X
Jin, 2004^116^ | X
Johansson, 2014^117^ | | X
Johansson, 2019^118^ | | X
Kalinowski, 2019^119^ | | | X
Kanazawa, 2019^120^ | X
Kanis, 2002^121^ | | X
Kanis, 2007^122^ | X
Kaptoge, 2004^123^ | | X
Kaptoge, 2006^124^ | X
Katon, 2015^125^ | X
Kauppi, 2013^126^ | | X
Kennedy, 2014^127^ | | X
Khatib, 2018^128^ | | | | | X
Kimber , 2011^129^ | | | | X
Kirk, 2018^130^ | | X
Kleiber Balderrama, 2017^131^ | | | X
Klop, 2015^132^ | | X
Klop, 2016^133^ | X
Knobe, 2018^134^ | | | | X
Korpi-Steiner, 2014^135^ | | | | | | | X
Krege, 2013^136^ | | X
Krupski, 2004^137^ | | X
Kruse, 2017^138^ | | X
Kung, 2005^139^ | | | | | | | X
LaFleur, 2015^140^ | X
LaFleur, 2018^141^ | X
Lalmohamed, 2012^142^ | | X
Lam, 2020^143^ | | | | | | | X
Langsetmo, 2011^144^ | | X
Langsetmo, 2018^145^ | | X
Lapi, 2012^146^ | | X
Lazo, 2001^147^ | | | | | X
Lazzari, 2013^148^ | | X
Lee, 2010^149^ | | X
Lee, 2012^150^ | X
Lee, 2014^151^ | | | | X
Lee, 2015^152^ | X
Leib, 2014^153^ | | X
Leslie , 2010^154^ | X
Leslie , 2010^155^ | | X
Leslie , 2010^156^ | | X
Leslie , 2011^157^ | | X
Leslie , 2011^158^ | | X
Leslie , 2011^159^ | | X
Leslie , 2012^160^ | | X
Leslie , 2013^161^ | | X
Leslie , 2014^162^ | | X
Leslie , 2016^163^ | | X
Leslie , 2017^164^ | | X
Leslie , 2018^165^ | | X
Leslie , 2019^166^ | | X
Leslie, 2019^167^ | | X
Leslie, 2020^168^ | X
Leslie, 2020^169^ | X
Li, 2014^170^ | | | | | | | X
Lim, 2016^171^ | | X
Lin, 2016^172^ | | | | | | | X
Lin, 2017^173^ | | | | | | | X
Lindgren, 2017^174^ | | X
Lippuner, 2009^175^ | X
Lippuner, 2010^176^ | | | | X
Liu, 2011^177^ | | | | | | | X
Lix, 2011^178^ | X
Li-Yu, 2005^179^ | | | | | | | X
Looker , 2008^180^ | | X
López, 2005^181^ | | X
López-Larramona, 2015^182^ | | | | | X
Luukinen, 2000^183^ | | X
Lynn, 2005^184^ | | | | | | | X
Lynn, 2008^185^ | | | | | | | X
Ma, 2016^186^ | | | | | | | X
Madore, 2004^187^ | | | | | | | X
Magnus , 2008^188^ | | X
Majumdar, 2016^189^ | X
Marques, 2017^190^ | | X
Martineau, 2018^191^ | | X
Mazzantini, 2010^192^ | | X
McCarthy, 2015^193^ | | | | | X
McDiarmid, 2018^194^ | X
McDonald, 2016^195^ | | | | X
Meier, 2005^196^ | | X
Melcer, 2017^197^ | | | | X
Melton, 2012^198^ | | X
Michalski, 2019^199^ | | | | | | | X
Montagnani, 2001^200^ | | X
Morse, 2009^201^ | | X
Morse, 2009^202^ | X
Mrgan, 2013^203^ | X
Nassar, 2014^204^ | | X
Nayak , 2016^205^ | | | | | X
Naylor, 2015^206^ | X
Nethander, 2020^207^ | | X
Neubecker, 2011^208^ | X
Nguyen, 2007^209^ | | X
Nicoll, 2016^210^ | | | | X
Ogunwale, 2020^211^ | | | | X
Ogura-Tomomatsu, 2012^212^ | | | | | X
Pang , 2014^213^ | X
Paniagua, 2006^214^ | | | | | X
Park, 2013^215^ | X
Park, 2016^216^ | X
Pasco, 2014^217^ | | X
Patil, 2021^218^ | | X
Pepe, 2012^219^ | | | | | X
Pérez-Castrillón, 2007^220^ | | X
Pham, 2016^221^ | | X
Pluskiewicz, 2014^222^ | | X
Poh, 2008^223^ | X
Poór, 1995^224^ | | X
Pourmalek, 2017^225^ | | | X
Przedlacki, 2018^226^ | X
Pundole, 2018^227^ | | | | X
Ranstam, 1996^228^ | | X
Reber, 2018^229^ | X
Rendl, 2013^230^ | X
Richards, 2007^231^ | | X
Riggs, 2006^232^ | | X
Rodondi, 2012^233^ | X
Roig Vilaseca, 2011^234^ | | X
Rotondi, 2016^235^ | X
Roumie, 2005^236^ | X
Routh, 2005^237^ | | X
Roux, 2014^238^ | X
Rubin, 2018^239^ | | | | X
Rudman, 1994^240^ | | | | | X
Salvig, 2016^241^ | | X
Samelson, 2019^242^ | | X
Sandhu, 2010^243^ | | | | | X
Sanfelix-Genoves, 2010^244^ | | | | | X
Satyaraddi, 2017^245^ | | | | | | | X
Schmidt, 2019^246^ | X
Schousboe, 2013^247^ | | | X
Schousboe, 2016^248^ | | X
Schwartz, 2011^249^ | | X
Schwartz, 2013^250^ | | X
Shahla, 2011^251^ | | | | | | | X
Shan-Fu, 2017^252^ | | | | | | | X
Sheer, 2020^253^ | X
Shojaei, 2006^254^ | | | | | | | X
Sieber, 2012^255^ | | X
Siggeirsdottir, 2014^256^ | | | | X
Siminoski, 2007^257^ | | | | | | | X
Slemenda, 1992^258^ | | | X
Smith, 2005^259^ | X
Stanley, 1991^260^ | | | | | X
Starr, 2019^261^ | | X
Starup-Linde, 2016^262^ | | X
Stefanovics, 2018^263^ | X
Stehman-Breen, 2001^264^ | | | | | X
Stephens, 2016^265^ | | X
Stockbrügger, 2002^266^ | X
Su, 2017^267^ | | | | | | | X
Su, 2017^268^ | | | | | | | X
Su, 2018^269^ | | | | | | | X
Su, 2019^270^ | | | | | | | X
Su, 2019^271^ | | X
Sutton, 2020^272^ | | | | | | | X
Szulc, 2005^273^ | | X
Tang, 2007^274^ | | | | | | | X
Taylor, 2016^275^ | | X
Timmer, 2009^276^ | X
Torstensson, 2015^277^ | | X
Tortora, 2018^278^ | | | | | X
Travers-Gustafson, 1995^279^ | | X
Tugcu, 2009^280^ | | | | | X
Välimäki, 2005^281^ | | | X
Välimäki, 2006^282^ | | X
van der Veer, 2014^283^ | | | | X
van Staa, 2002^284^ | | X
van Varsseveld, 2015^285^ | | X
Vanderschueren, 2000^286^ | | | | | | | X
Verdijk, 2009^287^ | X
Vokes, 2003^288^ | X
Vokes, 2010^289^ | | X
Waljee, 2016^290^ | | | | | X
Wang, 2012^291^ | | X
Ward, 2014^292^ | X
Wehrli, 2000^293^ | | X
Westfall, 2001^294^ | | X
Wilcox, 2006^295^ | | X
Wildberger, 2017^296^ | | | | | | | X
Wilson, 2009^297^ | | | | | | | X
Woo, 2004^298^ | | X
Wu, 2020^299^ | | X
Xu, 2020^300^ | X
Yang, 2015^301^ | | | | | | | X
Yang, 2017^302^ | X
Yaturu, 2009^303^ | | X
Yazdanpanah, 2007^304^ | X
Ye, 2020^305^ | | X
Yeh, 2002^306^ | | | | | X
Yoon, 2010^307^ | X
Yu, 2017^308^ | | | | | | | X
Zhang, 2012^309^ | | | | | | | X
Zhang, 2016^310^ | | | | | | | X
Zhang, 2018^311^ | | | | | | | X
Zhang, 2018^312^ | | | | | X
Zhong, 2017^313^ | | | | | | | X
Zhou, 2016^314^ | | X
Zhu, 2011^315^ | X

## REFERENCES TO APPENDIX D

1 Abderhalden L, Weaver FM, Bethel M, . Dual-energy X-ray absorptiometry and fracture prediction in patients with spinal cord injuries and disorders. Osteoporos Int. 2017;28(3):925–934.27924381
2 Ackman JM, Lata PF, Schuna AA, Elliott ME. Bone health evaluation in a veteran population: a need for the Fracture Risk Assessment Tool (FRAX). Ann Pharmacother. 2014;48(10):1288–1293.24994725
3 Adami S, Giannini S, Giorgino R, . The effect of age, weight, and lifestyle factors on calcaneal quantitative ultrasound: The ESOPO study. Osteoporos Int. 2003;14(3):198–207.12730794
4 Adams AL, Li BH, Bhandari S, . Chronic hyponatremia and association with osteoporosis among a large racially/ethnically diverse population. Osteoporos Int. 2019;30(4):853–861.30635697
5 Adler RA, Funkhouser HL, Petkov VI, . Osteoporosis in pulmonary clinic patients: Does point-of-care screening predict central dual-energy x-ray absorptiometry? Chest. 2003;123(6):2012–2018.12796183
6 Aguirre LE, Colleluori G, Dorin R, . Hypogonadal Men with Higher Body Mass Index have Higher Bone Density and Better Bone Quality but Reduced Muscle Density. Calcif Tissue Int. 2017;101(6):602–611.28856390
7 Alajlouni D, Bliuc D, Tran T, Eisman JA, Nguyen TV, Center JR. Decline in Muscle Strength and Performance Predicts Fracture Risk in Elderly Women and Men. J Clin Endocrinol Metab. 2020;105(9).
8 Albaba M, Cha SS, Takahashi PY. The Elders Risk Assessment Index, an electronic administrative database-derived frailty index, can identify risk of hip fracture in a cohort of community-dwelling adults. Mayo Clin Proc. 2012;87(7):652–658.22766085
9 Albright P, Du P, Haas RE, Pugh LC. Evidence-based screening for low bone mineral density in HIV-infected men. J Assoc Nurses AIDS Care. 2014;25(6):532–540.24823286
10 Alcalde Vargas A, Pascasio Acevedo JM, Gutierrez Domingo I, . Prevalence and characteristics of bone disease in cirrhotic patients under evaluation for liver transplantation. Transplant Proc. 2012;44(6):1496–1498.22841194
11 Allin S, Bleakney R, Zhang J, Munce S, Cheung AM, Jaglal S. Evaluation of Automated Fracture Risk Assessment Based on the Canadian Association of Radiologists and Osteoporosis Canada Assessment Tool. J Clin Densitom. 2016;19(3):332–339.27067299
12 Almog YA, Rai A, Zhang P, . Deep Learning With Electronic Health Records for Short-Term Fracture Risk Identification: Crystal Bone Algorithm Development and Validation. J Med Internet Res. 2020;22(10):e22550.32956069
13 Amin S, Felson DT. Osteoporosis in men. Rheumatic Disease Clinics of North America. 2001;27(1):19–47.11285995
14 Andersen S, Laurberg P. Age impact on clinical risk factors does not justify the age related change in referral pattern for osteoporosis assessment - Data from the Aalborg University Hospital Record for Osteoporosis Risk Assessment (AURORA). Maturitas. 2015;80(3):302–307.25636241
15 Arabi A, Salamoun M, Ballout H, Fuleihan Gel H. Densitometer type and impact on risk assessment for osteoporosis. J Clin Densitom. 2005;8(3):261–266.16055954
16 Asirvatham AR, Balachandran K, Kannan S, Balasubramaniam SK, Mahadevan S. FRAX first-Pragmatic approach in resource poor settings. Indian J Endocrinol Metab. 2019;22(6):757–759.
17 Aspray TJ, Stevenson P, Abdy SE, Rawlings DJ, Holland T, Francis RM. Low bone mineral density measurements in care home residents - A treatable cause of fractures. Age Ageing. 2006;35(1):37–41.16364932
18 Aubry-Rozier B, Stoll D, Krieg MA, Lamy O, Hans D. What was your fracture risk evaluated by FRAX(R) the day before your osteoporotic fracture? Clin Rheumatol. 2013;32(2):219–223.23114631
19 Aynardi M, Ilyas AM. Pharmacologic management of osteoporosis. J Hand Surg Am. 2013;38(3):588–592.23312206
20 Ayres LRO, Clarke S, Digby-Bell J, . Fragility fracture risk in cirrhosis: A comparison of the fracture risk assessment tool, British Society of Gastroenterology and National Institute for Health and Clinical Excellence guidelines. Frontline Gastroenterology. 2012;3(4):220–227.28839671
21 Barbour KE, Zmuda JM, Strotmeyer ES, . Correlates of trabecular and cortical volumetric bone mineral density of the radius and tibia in older men: The osteoporotic fractures in men study. J Bone Miner Res. 2010;25(5):1017–1028.20200975
22 Barrett-Connor E, Laughlin GA, Li H, . The association of concurrent vitamin D and sex hormone deficiency with bone loss and fracture risk in older men: The osteoporotic fractures in men (MrOS) study. J Bone Miner Res. 2012;27(11):2306–2313.22777902
23 Bass E, Pracht E, Foulis P. Bone mineral density scans in veterans. Clin Interv Aging. 2007;2(2):255–261.18044141
24 Bauer DC, Garnero P, Harrison SL, . Biochemical markers of bone turnover, hip bone loss, and fracture in older men: The MrOS study. J Bone Miner Res. 2009;24(12):2032–2038.19453262
25 Beaton DE, Vidmar M, Pitzul KB, . Addition of a fracture risk assessment to a coordinator’s role improved treatment rates within 6 months of screening in a fragility fracture screening program. Osteoporos Int. 2017;28(3):863–869.27770155
26 Beattie KA, Ioannidis G, MacDermid JC, . Appropriate osteoporosis treatment by family physicians in response to FRAX vs CAROC reporting: results from a randomized controlled trial. J Clin Densitom. 2014;17(4):458–465.24206869
27 Beattie K, Adachi J, Ioannidis G, . Estimating osteoporotic fracture risk following a wrist fracture: a tale of two systems. Arch Osteoporos. 2015;10:13.25957065
28 Beaudoin C, Moore L, Gagne M, . Performance of predictive tools to identify individuals at risk of non-traumatic fracture: a systematic review, meta-analysis, and meta-regression. Osteoporos Int. 2019;30(4):721–740.30877348
29 Beck TJ, Ruff CB, Mourtada FA, . Dual-energy X-ray absorptiometry derived structural geometry for stress fracture prediction in male U.S. marine corps recruits. J Bone Miner Res. 1996;11(5):645–653.9157779
30 Bedimo R, Maalouf NM, Zhang S, Drechsler H, Tebas P. Osteoporotic fracture risk associated with cumulative exposure to tenofovir and other antiretroviral agents. AIDS. 2012;26(7):825–831.22301411
31 Berry SD, Kiel DP. Absolute risk of subsequent fracture was similar in women and men. Evid Based Med. 2007;12(4):123.17885171
32 Bethel M, Weaver FM, Bailey L, . Risk factors for osteoporotic fractures in persons with spinal cord injuries and disorders. Osteoporos Int. 2016;27(10):3011–3021.27230522
33 Bethel M, Bailey L, Weaver F, . A historical study of appendicular fractures in veterans with traumatic chronic spinal cord injury: 2002-2007. J Spinal Cord Med. 2016;39(6):686–692.26899918
34 Bethel M, Buzkova P, Fink HA, . Soluble CD14 and fracture risk. Osteoporos Int. 2016;27(5):1755–1763.26659065
35 Bhat KA, Kakaji M, Awasthi A, . Utility of Osteoporosis Self-Assessment Tool as a Screening Tool for Predicting Osteoporosis in Indian Men. J Clin Densitom. 2017;20(2):160–163.27210803
36 Bisson EJ, Finlayson ML, Ekuma O, Marrie RA, Leslie WD. Accuracy of FRAX® in People With Multiple Sclerosis. J Bone Miner Res. 2019.
37 Blanchard M, Molina-Vicenty HD, Stein PK, . Medical Correlates of Chronic Multisymptom Illness in Gulf War Veterans. Am J Med. 2019;132(4):510–518.30576630
38 Blomeier H, Larry Jameson J. Weight loss increases bone loss in older men. Postgrad Med. 2005;118(1).
39 Bolton J, Morin SN, Majumdar SR, . Association of Mental Disorders and Related Medication Use With Risk for Major Osteoporotic Fractures. JAMA Psychiatry. 2017;74(6):641–648.28423154
40 Borade A, Kempegowda H, Tawari A, Suk M, Horwitz DS. Improvement in osteoporosis detection in a fracture liaison service with integration of a geriatric hip fracture care program. Injury. 2016;47(12):2755–2759.27773370
41 Bours S, de Vries F, van den Bergh JPW, . Risk of vertebral and non-vertebral fractures in patients with sarcoidosis: a population-based cohort. Osteoporos Int. 2016;27(4):1603–1610.26630976
42 Bow CH, Tsang SW, Loong CH, Soong CS, Yeung SC, Kung AW. Bone mineral density enhances use of clinical risk factors in predicting ten-year risk of osteoporotic fractures in Chinese men: the Hong Kong Osteoporosis Study. Osteoporos Int. 2011;22(11):2799–2807.21234548
43 Brinton DL, Simpson AN, Fominaya CE, LaRue AC. Impact of selective serotonin reuptake inhibitors in the veteran population: 10-year risk outcomes. J Comp Eff Res. 2019;8(6):431–440.30855179
44 Broussard DL, Magnus JH. Risk assessment and screening for low bone mineral density in a multi-ethnic population of women and men: does one approach fit all? Osteoporos Int. 2004;15(5):349–360.14676991
45 Broussard DL, Magnus JH. Coronary heart disease risk and bone mineral density among U.S. women and men. J Womens Health. 2008;17(3):479–490.
46 Calmy A, Fux CA, Norris R, . Low bone mineral density, renal dysfunction, and fracture risk in HIV infection: A cross-sectional study. J Infect Dis. 2009;200(11):1746–1754.19874178
47 Caplan L, Hines AE, Williams E, . An observational study of glucocorticoid-induced osteoporosis prophylaxis in a national cohort of male veterans with rheumatoid arthritis. Osteoporos Int. 2011;22(1):305–315.20358362
48 Carnevale V, Morano S, Fontana A, . Assessment of fracture risk by the FRAX algorithm in men and women with and without type 2 diabetes mellitus: a cross-sectional study. Diabetes Metab Res Rev. 2014;30(4):313–322.24420974
49 Caughey GE, Roughead EE, Shakib S, McDermott RA, Vitry AI, Gilbert AL. Comorbidity of chronic disease and potential treatment conflicts in older people dispensed antidepressants. Age Ageing. 2010;39(4):488–494.20511245
50 Cervinka T, Lynch CL, Giangregorio L, . Agreement between fragility fracture risk assessment algorithms as applied to adults with chronic spinal cord injury. Spinal Cord. 2017;55(11):985–993.28607522
51 Chalhoub D, Cawthon PM, Ensrud KE, . Risk of Nonspine Fractures in Older Adults with Sarcopenia, Low Bone Mass, or Both. J Am Geriatr Soc. 2015;63(9):1733–1740.26310882
52 Chalhoub D, Orwoll ES, Cawthon PM, . Areal and volumetric bone mineral density and risk of multiple types of fracture in older men. Bone. 2016;92:100–106.27554426
53 Chan MY, Nguyen ND, Center JR, Eisman JA, Nguyen TV. Absolute fracture-risk prediction by a combination of calcaneal quantitative ultrasound and bone mineral density. Calcif Tissue Int. 2012;90(2):128–136.22179560
54 Chang SF, Yang RS. Optimal Analysis to Discriminate Males’ Osteoporosis With Simple Physiological Indicators: A Cutoff Point Study. Am J Mens Health. 2016;10(6):487–494.25766506
55 Chang AJ, Ying Q, Chen XN, Wang WM, Chen N. Evaluation of three risk assessment tools in discriminating fracture status among Chinese patients undergoing hemodialysis. Osteoporos Int. 2016;27(12):3599–3606.27392466
56 Chao YP, Kao TW, Chen WL, Peng TC, Wu LW. Mid-arm muscle circumference as an indicator of osteoporosis in community-dwelling older men. Arch Gerontol Geriatr. 2020;87:103998.31877529
57 Chen JS, Simpson JM, Blyth FM, March LM. Managing osteoporosis with FRAX(R) in Australia: proposed new treatment thresholds from the 45&Up Study cohort. Bone. 2014;69:148–153.25263521
58 Chen CH, Lin CL, Kao CH. Association Between Chronic Hepatitis B Virus Infection and Risk of Osteoporosis: A Nationwide Population-Based Study. Medicine (Baltimore). 2015;94(50):e2276.26683953
59 Chen SJ, Chen YJ, Cheng CH, Hwang HF, Chen CY, Lin MR. Comparisons of Different Screening Tools for Identifying Fracture/Osteoporosis Risk Among Community-Dwelling Older People. Medicine (Baltimore). 2016;95(20):e3415.27196447
60 Cheng CK, McDonald-Blumer H, Boire G, . Care gap in patients with early inflammatory arthritis with a high fracture risk identified using FRAX((R)). J Rheumatol. 2010;37(11):2221–2225.20716658
61 Chuang MH, Chuang TL, Koo M, Wang YF. Low Hemoglobin Is Associated With Low Bone Mineral Density and High Risk of Bone Fracture in Male Adults: A Retrospective Medical Record Review Study. American journal of men’s health. 2019;13(3):1557988319850378.
62 Cirnigliaro CM, Myslinski MJ, Asselin P, . Progressive Sublesional Bone Loss Extends into the Second Decade After Spinal Cord Injury. J Clin Densitom. 2019;22(2):185–194.30503961
63 Clarke S, Bradley R, Simmonds B, . Can paramedics use FRAX (the WHO Fracture Risk Assessment Tool) to help GPs improve future fracture risk in patients who fall? Protocol for a randomised controlled feasibility study. BMJ Open. 2014;4.
64 Colon-Emeric CS, Pieper CF, Artz MB. Can historical and functional risk factors be used to predict fractures in community-dwelling older adults? development and validation of a clinical tool. Osteoporos Int. 2002;13(12):955–961.12459938
65 Colon-Emeric CS, Pieper CF, Van Houtven CH, . Limited Osteoporosis Screening Effectiveness Due to Low Treatment Rates in a National Sample of Older Men. Mayo Clin Proc. 2018;93(12):1749–1759.30497697
66 Couraud G, Souffir C, Gaigneux E, Kolta S, Roux C, Briot K. Adjusting FRAX® on TBS for identification of subjects at high risk of fractures. Bone. 2017;101:214–218.28479495
67 Couris CM, Chapurlat RD, Kanis JA, . FRAX® probabilities and risk of major osteoporotic fracture in France. Osteoporos Int. 2012;23(9):2321–2327.22179418
68 Cronholm F, Rosengren BE, Nilsson JA, . The fracture predictive ability of a musculoskeletal composite score in old men - data from the MrOs Sweden study. BMC Geriatr. 2019;19(1):90.30902044
69 De Laet CE, Van Hout BA, Burger H, Weel AE, Hofman A, Pols HA. Hip fracture prediction in elderly men and women: validation in the Rotterdam study. J Bone Miner Res. 1998;13(10):1587–1593.9783547
70 Dell RM, Greene D, Anderson D, Williams K. Osteoporosis disease management: What every orthopaedic surgeon should know. Journal of Bone and Joint Surgery - Series A. 2009;91(SUPPL. 6):79–86.
71 Derkatch S, Kirby C, Kimelman D, Jozani MJ, Davidson JM, Leslie WD. Identification of Vertebral Fractures by Convolutional Neural Networks to Predict Nonvertebral and Hip Fractures: A Registry-based Cohort Study of Dual X-ray Absorptiometry. Radiology. 2019;293(2):405–411.31526255
72 Dicken AJ, Evans JP, Rogers KD, . Classification of fracture and non-fracture groups by analysis of coherent X-ray scatter. Sci Rep. 2016;6:29011.27363947
73 Duncan R, Francis RM, Jagger C, . Magnitude of fragility fracture risk in the very old—are we meeting their needs? The Newcastle 85+ Study. Osteoporos Int. 2014;26(1):123–130.25224291
74 E E, Wang T, Yang L, . Machine Learning Can Improve Clinical Detection of Low BMD: The DXA-HIP Study. J Clin Densitom. 2020.
75 Edwards MH, Jameson K, Denison H, . Clinical risk factors, bone density and fall history in the prediction of incident fracture among men and women. Bone. 2013;52(2):541–547.23159464
76 El Maghraoui A, Roux C. DXA scanning in clinical practice. QJM. 2008;101(8):605–617.18334497
77 El-Gabalawy R, Blaney C, Tsai J, Sumner JA, Pietrzak RH. Physical health conditions associated with full and subthreshold PTSD in U.S. military veterans: Results from the National Health and Resilience in Veterans Study. J Affect Disord. 2018;227:849–853.29689700
78 Elliott ME, Farrah RM, Binkley NC, Carnes ML, Gudmundsson A. Management of glucocorticoid-induced osteoporosis in male veterans. Ann Pharmacother. 2000;34(12):1380–1384.11144692
79 Ensrud KE, Taylor BC, Peters KW, . Implications of expanding indications for drug treatment to prevent fracture in older men in United States: cross sectional and longitudinal analysis of prospective cohort study. BMJ. 2014;349:g4120.24994809
80 Faulkner KA, Chan BK, Cauley JA, . Histories including number of falls may improve risk prediction for certain non-vertebral fractures in older men. Inj Prev. 2009;15(5):307–311.19805598
81 Fink HA, Kuskowski MA, Marshall LM. Association of stressful life events with incident falls and fractures in older men: The osteoporotic fractures in men (MrOS) Study. Age Ageing. 2014;43(1):103–108.24002237
82 Forgetta V, Keller-Baruch J, Forest M, . Development of a polygenic risk score to improve screening for fracture risk: A genetic risk prediction study. PLoS Med. 2020;17(7):e1003152.32614825
83 Fransiska Y, Tiksnadi B, Chaidir R, Ismiarto YD. The male osteoporosis risk estimation score and the osteoporosis self-assessment screening tool for Indonesian men. J Orthop Surg (Hong Kong). 2012;20(2):205–208.22933680
84 Fraser LA, Langsetmo L, Berger C, . Fracture prediction and calibration of a Canadian FRAX(R) tool: a population-based report from CaMos. Osteoporos Int. 2011;22(3):829–837.21161508
85 Frost SA, Nguyen ND, Center JR, Eisman JA, Nguyen TV. Timing of repeat BMD measurements: development of an absolute risk-based prognostic model. J Bone Miner Res. 2009;24(11):1800–1807.19419321
86 Fu Y, Li C, Luo W, Chen Z, Liu Z, Ding Y. Fragility fracture discriminative ability of radius quantitative ultrasound: a systematic review and meta-analysis. Osteoporos Int. 2021;32(1):23–38.32728897
87 Funkhouser HL, Adera T, Adler RA. Effect of HMG-CoA reductase inhibitors (statins) on bone mineral density. J Clin Densitom. 2002;5(2):151–158.12110758
88 Gadam RK, Schlauch K, Izuora KE. Frax prediction without BMD for assessment of osteoporotic fracture risk. Endocr Pract. 2013;19(5):780–784.24121261
89 Geusens PPM, Van Den Bergh JP. Bone: New guidelines for multistep fracture prevention in men. Nature Reviews Rheumatology. 2012;8(10):568–570.
90 Giangregorio LM, Leslie WD, Lix LM, . FRAX underestimates fracture risk in patients with diabetes. J Bone Miner Res. 2012;27(2):301–308.22052532
91 Gielen E, O’Neill T, Pye S, . Bone turnover markers predict hip bone loss in elderly European men: results of the European Male Ageing Study (EMAS). Osteoporos Int. 2014;26(2):617–627.25224294
92 Gill US, Zissimopoulos A, Al-Shamma S, . Assessment of bone mineral density in tenofovir-treated patients with chronic hepatitis B: Can the fracture risk assessment tool identify those at greatest risk? J Infect Dis. 2015;211(3):374–382.25156561
93 Gimigliano F, Moretti A, Riccio I, Letizia Mauro G, Gimigliano R, Iolascon G. Classification of functioning and assessment of fracture risk of a large Italian osteoporotic population. The Physiatric Approach To Osteoporosis project. Eur J Phys Rehabil Med. 2015;51(5):529–538.25994371
94 Gómez Alonso C, Díaz Curiel M, Hawkins Carranza F, Pérez Cano R, Díez Pérez A. Femoral bone mineral density, neck-shaft angle and mean femoral neck width as predictors of hip fracture in men and women. Osteoporos Int. 2000;11(8):714–720.
95 Gotthardt F, Huber C, Thierfelder C, . Bone mineral density and its determinants in men with opioid dependence. J Bone Miner Metab. 2017;35(1):99–107.26747613
96 Gould H, Brennan SL, Nicholson GC, Kotowicz MA, Henry MJ, Pasco JA. Calcaneal ultrasound reference ranges for Australian men and women: the Geelong Osteoporosis Study. Osteoporos Int. 2013;24(4):1369–1377.22814945
97 Gourlay ML, Overman RA, Fine JP, . Time to Osteoporosis and Major Fracture in Older Men: The MrOS Study. Am J Prev Med. 2016;50(6):727–736.26821835
98 Greenwald L, Barajas K, White-Greenwald M. Better bone density reporting: T-score report versus fracture risk report with outcome analysis. Am J Manag Care. 2003;9(10):665–670.14572176
99 Gruber M, Bauer JS, Dobritz M, . Bone mineral density measurements of the proximal femur from routine contrast-enhanced MDCT data sets correlate with dual-energy X-ray absorptiometry. Eur Radiol. 2013;23(2):505–512.22932742
100 Gupta A, Greening NJ, Evans RA, Samuels A, Toms N, Steiner MC. Prospective risk of osteoporotic fractures in patients with advanced chronic obstructive pulmonary disease. Chron Respir Dis. 2019;16.
101 Hanusch BC, Tuck SP, McNally RJQ, . Does regional loss of bone density explain low trauma distal forearm fractures in men (the Mr F study)? Osteoporos Int. 2017;28(10):2877–2886.28685278
102 Harvey NC, Oden A, Orwoll E, . Measures of Physical Performance and Muscle Strength as Predictors of Fracture Risk Independent of FRAX, Falls, and aBMD: A Meta-Analysis of the Osteoporotic Fractures in Men (MrOS) Study. J Bone Miner Res. 2018;33(12):2150–2157.30011086
103 Harvey NC, Odén A, Orwoll E, . Falls Predict Fractures Independently of FRAX Probability: A Meta-Analysis of the Osteoporotic Fractures in Men (MrOS) Study. J Bone Miner Res. 2018;33(3):510–516.29220072
104 Hayashi T, Joki N, Tanaka Y, . The FRAX (R) as a predictor of mortality in Japanese incident hemodialysis patients: an observational, follow-up study. J Bone Miner Metab. 2015;33(6):674–683.25691284
105 Hoff M, Skurtveit S, Meyer HE, . Anti-osteoporosis drug use: too little, too much, or just right? The HUNT study, Norway. Osteoporos Int. 2018;29(8):1875–1885.29774403
106 Ho-Le TP, Center JR, Eisman JA, Nguyen HT, Nguyen TV. Prediction of Bone Mineral Density and Fragility Fracture by Genetic Profiling. J Bone Miner Res. 2017;32(2):285–293.27649491
107 Holloway KL, Kotowicz MA, Lane SE, Brennan SL, Pasco JA. FRAX (Aus) and falls risk: Association in men and women. Bone. 2015;76:1–4.25771422
108 Holloway KL, Mohebbi M, Betson AG, . Prediction of major osteoporotic and hip fractures in Australian men using FRAX scores adjusted with trabecular bone score. Osteoporos Int. 2018;29(1):101–108.28940052
109 Holloway-Kew KL, Betson A, Rufus-Membere PG, . Impact microindentation in men with impaired fasting glucose and type 2 diabetes. Bone. 2021;142:115685.33049369
110 Hsu CY, Wu CH, Yu SF, . Novel algorithm generating strategy to identify high fracture risk population using a hybrid intervention threshold. J Bone Miner Metab. 2020;38(2):213–221.31583541
111 Huang JY, Song WZ, Huang M. Effectiveness of Osteoporosis Self-Assessment Tool for Asians in Screening for Osteoporosis in Healthy Males Over 40 Years Old in China. J Clin Densitom. 2017;20(2):153–159.28153410
112 Jain R, Vokes T. African Americans have lower TBS than whites among densitometry patients at a Chicago academic center. Osteoporos Int. 2017;28(3):917–923.27743070
113 Jamal SA, West SL, Nickolas TL. The clinical utility of FRAX to discriminate fracture status in men and women with chronic kidney disease. Osteoporos Int. 2014;25(1):71–76.24114399
114 Jefferies ER, Bahl A, Hounsome L, Eylert MF, Verne J, Persad RA. Admissions to hospital due to fracture in England in patients with prostate cancer treated with androgen-deprivation therapy - do we have to worry about the hormones? BJU Int. 2016;118(3):416–422.26857695
115 Jehle S, Hulter HN, Krapf R. Effect of potassium citrate on bone density, microarchitecture, and fracture risk in healthy older adults without osteoporosis: a randomized controlled trial. J Clin Endocrinol Metab. 2013;98(1):207–217.23162100
116 Jin H, Lu Y, Harris ST, . Classification algorithms for hip fracture prediction based on recursive partitioning methods. Med Decis Making. 2004;24(4):386–398.15271277
117 Johansson H, Oden A, Karlsson MK, . Waning predictive value of serum adiponectin for fracture risk in elderly men: MrOS Sweden. Osteoporos Int. 2014;25(7):1831–1836.24809807
118 Johansson M, Ricci F, Di Martino G, . Cardiovascular biomarkers predict fragility fractures in older adults. Heart. 2019;105(6):449–454.30322844
119 Kalinowski P, Rozylo-Kalinowska I, Piskorz M, Bojakowska-Komsta U. Correlations between periodontal disease, mandibular inferior cortex index and the osteoporotic fracture probability assessed by means of the fracture risk assessment body mass index tool. BMC Med Imaging. 2019;19(1):41.31117973
120 Kanazawa I, Tanaka KI, Takeo A, Notsu M, Miyake H, Sugimoto T. A scoring assessment tool for the risk of vertebral fractures in patients with type 2 diabetes mellitus. Bone. 2019;122:38–44.30763635
121 Kanis JA, Johnell O, Oden A, De Laet C, Jonsson B, Dawson A. Ten-year risk of osteoporotic fracture and the effect of risk factors on screening strategies. Bone. 2002;30(1):251–258.11792594
122 Kanis JA, Oden A, Johnell O, . The use of clinical risk factors enhances the performance of BMD in the prediction of hip and osteoporotic fractures in men and women. Osteoporos Int. 2007;18(8):1033–1046.17323110
123 Kaptoge S, Armbrecht G, Felsenberg D, . When should the doctor order a spine X-ray? Identifying vertebral fractures for osteoporosis care: Results from the European Prospective Osteoporosis Study (EPOS). J Bone Miner Res. 2004;19(12):1982–1993.15537441
124 Kaptoge S, Armbrecht G, Felsenberg D, . Whom to treat? The contribution of vertebral X-rays to risk-based algorithms for fracture prediction. Results from the European Prospective Osteoporosis Study. Osteoporos Int. 2006;17(9):1369–1381.16821002
125 Katon JG, Hoggatt KJ, Balasubramanian V, . Reproductive health diagnoses of women veterans using department of Veterans Affairs health care. Med Care. 2015;53(4 Suppl 1):S63–67.25767978
126 Kauppi M, Impivaara O, Maki J, Heliovaara M, Jula A. Quantitative ultrasound measurements and vitamin D status in the assessment of hip fracture risk in a nationally representative population sample. Osteoporos Int. 2013;24(10):2611–2618.23595563
127 Kennedy CC, Ioannidis G, Rockwood K, . A Frailty Index predicts 10-year fracture risk in adults age 25 years and older: results from the Canadian Multicentre Osteoporosis Study (CaMos). Osteoporos Int. 2014;25(12):2825–2832.25103215
128 Khatib J, Stote K, Gosmanov AR. Utility of DXA screening for diagnosis of osteoporosis in US veterans aged 70 years and older. J Investig Med. 2018;66(2):298–303.
129 Kimber C, Grimmer-Somers K. A novel primary care clinical prediction rule for early detection of osteoporosis. Australian Journal of Primary Health. 2011;17(2):175–180.21645474
130 Kirk PS, Borza T, Shahinian VB, . The implications of baseline bone-health assessment at initiation of androgen-deprivation therapy for prostate cancer. BJU Int. 2018;121(4):558–564.29124881
131 Kleiber Balderrama C, Rosenthal AK, Lans D, Singh JA, Bartels CM. Calcium Pyrophosphate Deposition Disease and Associated Medical Comorbidities: A National Cross-Sectional Study of US Veterans. Arthritis Care Res. 2017;69(9):1400–1406.
132 Klop C, Welsing PMJ, Leufkens HGM, . The Epidemiology of Hip and Major Osteoporotic Fractures in a Dutch Population of Community-Dwelling Elderly: Implications for the Dutch FRAX ® Algorithm. PLoS One. 2015;10(12).
133 Klop C, de Vries F, Bijlsma JW, Leufkens HG, Welsing PM. Predicting the 10-year risk of hip and major osteoporotic fracture in rheumatoid arthritis and in the general population: an independent validation and update of UK FRAX without bone mineral density. Ann Rheum Dis. 2016;75(12):2095–2100.26984006
134 Knobe M, Rasche P, Rentemeister L, . Evaluation of a simple screening tool for ambulant fall prevention. Der Unfallchirurg. 2018;121(11):901–910.29396590
135 Korpi-Steiner N, Milhorn D, Hammett-Stabler C. Osteoporosis in men. Clin Biochem. 2014;47(10–11):950–959.24726494
136 Krege JH, Wan X, Lentle BC, . Fracture risk prediction: importance of age, BMD and spine fracture status. Bonekey Rep. 2013;2:404.24228164
137 Krupski TL, Smith MR, Lee WC, . Natural history of bone complications in men with prostate carcinoma initiating androgen deprivation therapy. Cancer. 2004;101(3):541–549.15274067
138 Kruse C, Eiken P, Vestergaard P. Machine Learning Principles Can Improve Hip Fracture Prediction. Calcif Tissue Int. 2017;100(4):348–360.28197643
139 Kung AW, Ho AY, Ross PD, Reginster JY. Development of a clinical assessment tool in identifying Asian men with low bone mineral density and comparison of its usefulness to quantitative bone ultrasound. Osteoporos Int. 2005;16(7):849–855.15611839
140 LaFleur J, Steenhoek CL, Horne J, . Comparing fracture absolute risk assessment (FARA) tools: an osteoporosis clinical informatics tool to improve identification and care of men at high risk of first fracture. Ann Pharmacother. 2015;49(5):506–514.25712443
141 LaFleur J, Bress AP, Myers J, . Tenofovir-Associated Bone Adverse Outcomes among a US National Historical Cohort of HIV-Infected Veterans: Risk Modification by Concomitant Antiretrovirals. Infect Dis Ther. 2018;7(2):293–308.29492905
142 Lalmohamed A, Welsing PMJ, Lems WF, . Calibration of FRAX ® 3.1 to the Dutch population with data on the epidemiology of hip fractures. Osteoporos Int. 2012;23(3):861–869.22120910
143 Lam MT, Sing CW, Li GHY, Kung AWC, Tan KCB, Cheung CL. Development and Validation of a Risk Score to Predict the First Hip Fracture in the Oldest Old: A Retrospective Cohort Study. J Gerontol A Biol Sci Med Sci. 2020;75(5):980–986.31353417
144 Langsetmo L, Nguyen TV, Nguyen ND, . Independent external validation of nomograms for predicting risk of low-trauma fracture and hip fracture. CMAJ. 2011;183(2):E107–114.21173069
145 Langsetmo L, Peters KW, Burghardt AJ, . Volumetric Bone Mineral Density and Failure Load of Distal Limbs Predict Incident Clinical Fracture Independent HR-pQCT BMD and Failure Load Predicts Incident Clinical Fracture of FRAX and Clinical Risk Factors Among Older Men. J Bone Miner Res. 2018;33(7):1302–1311.29624722
146 Lapi F, Simonetti M, Michieli R, . Assessing 5-year incidence rates and determinants of osteoporotic fractures in primary care. Bone. 2012;50(1):85–90.21985999
147 Lazo MG, Shirazi P, Sam M, Giobbie-Hurder A, Blacconiere MJ, Muppidi M. Osteoporosis and risk of fracture in men with spinal cord injury. Spinal Cord. 2001;39(4):208–214.11420736
148 Lazzari AA, Dussault PM, Thakore-James M, . Prevention of bone loss and vertebral fractures in patients with chronic epilepsy--antiepileptic drug and osteoporosis prevention trial. Epilepsia. 2013;54(11):1997–2004.24010637
149 Lee SH, Khang YH, Lim KH, . Clinical risk factors for osteoporotic fracture: a population-based prospective cohort study in Korea. J Bone Miner Res. 2010;25(2):369–378.19594298
150 Lee R, Lyles K, Sloane R, Colon-Emeric C. The association of newer anticonvulsant medications and bone mineral density. Endocr Pract. 2012:1–22.
151 Lee JH, Suh YS, Koh JH, . The risk of osteoporotic fractures according to the FRAX model in Korean patients with rheumatoid arthritis. J Korean Med Sci. 2014;29(8):1082–1089.25120317
152 Lee HS, Lee SH, Chung YS, Yang HJ, Son YJ, Park SB. Usefulness of fracture risk assessment tool using lumbar bone mineral density in prediction of osteoporotic vertebral fracture. Journal of Korean Neurosurgical Society. 2015;58(4):346–349.26587188
153 Leib E, Winzenrieth R, Aubry-Rozier B, Hans D. Vertebral microarchitecture and fragility fracture in men: A TBS study. Bone. 2014;62:51–55.24361639
154 Leslie WD, Lix LM, Johansson H, Oden A, McCloskey E, Kanis JA. Independent clinical validation of a Canadian FRAX tool: fracture prediction and model calibration. J Bone Miner Res. 2010;25(11):2350–2358.20499367
155 Leslie WD, Lix LM. Simplified 10-year absolute fracture risk assessment: a comparison of men and women. J Clin Densitom. 2010;13(2):141–146.20435264
156 Leslie WD, O’Donnell S, Lagace C, . Population-based Canadian hip fracture rates with international comparisons. Osteoporos Int. 2010;21(8):1317–1322.19802507
157 Leslie WD, Berger C, Langsetmo L, . Construction and validation of a simplified fracture risk assessment tool for Canadian women and men: results from the CaMos and Manitoba cohorts. Osteoporos Int. 2011;22(6):1873–1883.20967422
158 Leslie WD, Morin S. Fracture burden in relation to low bone mineral density and FRAX((R)) probability. J Clin Densitom. 2011;14(3):279–285.21723761
159 Leslie WD, Lix LM, Langsetmo L, . Construction of a FRAX(R) model for the assessment of fracture probability in Canada and implications for treatment. Osteoporos Int. 2011;22(3):817–827.21161509
160 Leslie WD, Majumdar SR, Lix LM, . High fracture probability with FRAX usually indicates densitometric osteoporosis: implications for clinical practice. Osteoporos Int. 2012;23(1):391–397.21365460
161 Leslie WD, Lix LM, Wu X. Competing mortality and fracture risk assessment. Osteoporos Int. 2013;24(2):681–688.22736068
162 Leslie WD, Aubry-Rozier B, Lix LM, Morin SN, Majumdar SR, Hans D. Spine bone texture assessed by trabecular bone score (TBS) predicts osteoporotic fractures in men: The Manitoba Bone Density Program. Bone. 2014;67:10–14.24998455
163 Leslie WD, Majumdar SR, Lix LM, . Direct comparison of FRAX(R) and a simplified fracture risk assessment tool in routine clinical practice: a registry-based cohort study. Osteoporos Int. 2016;27(9):2689–2695.27108119
164 Leslie WD, Majumdar SR, Morin SN, . FRAX for fracture prediction shorter and longer than 10 years: the Manitoba BMD registry. Osteoporos Int. 2017;28(9):2557–2564.28593449
165 Leslie WD, Majumdar SR, Morin SN, . Performance of FRAX in clinical practice according to sex and osteoporosis definitions: the Manitoba BMD registry. Osteoporos Int. 2018;29(3):759–767.29404625
166 Leslie WD, Luo Y, Yang S, . Fracture Risk Indices From DXA-Based Finite Element Analysis Predict Incident Fractures Independently From FRAX: The Manitoba BMD Registry. J Clin Densitom. 2019.
167 Leslie WD, Morin SN, Lix LM, . Fracture prediction from self-reported falls in routine clinical practice: a registry-based cohort study. Osteoporos Int. 2019;30(11):2195–2203.31372711
168 Leslie WD, Schousboe JT, Morin SN, . Measured height loss predicts incident clinical fractures independently from FRAX: a registry-based cohort study. Osteoporos Int. 2020;31(6):1079–1087.32016485
169 Leslie WD, Schousboe JT, Morin SN, . Loss in DXA-estimated total body lean mass but not fat mass predicts incident major osteoporotic fracture and hip fracture independently from FRAX: a registry-based cohort study. Arch Osteoporos. 2020;15(1):96.32588147
170 Li M, Hu Y, Xie J. Analysis of the complications of the collum femoris preserving (CFP) prostheses. Acta Orthop Traumatol Turc. 2014;48(6):623–627.25637725
171 Lim Y, Chun S, Lee J, . Association of bone mineral density and diabetic retinopathy in diabetic subjects: the 2008-2011 Korea National Health and Nutrition Examination Survey. Osteoporos Int. 2016;27(7):2249–2257.26883444
172 Lin J, Yang Y, Fei Q, . Validation of three tools for identifying painful new osteoporotic vertebral fractures in older chinese men: Bone mineral density, osteoporosis self-assessment tool for Asians, and fracture risk assessment tool. Clin Interv Aging. 2016;11:461–469.27217730
173 Lin J, Yang Y, Zhang X, . BFH-OSTM, a new predictive screening tool for identifying osteoporosis in elderly Han Chinese males. Clin Interv Aging. 2017;12:1167–1174.28814842
174 Lindgren E, Karlsson MK, Lorentzon M, Rosengren BE. Bone Traits Seem to Develop Also During the Third Decade in Life-Normative Cross-Sectional Data on 1083 Men Aged 18-28 Years. J Clin Densitom. 2017;20(1):32–43.27546559
175 Lippuner K, Johansson H, Kanis JA, Rizzoli R. Remaining lifetime and absolute 10-year probabilities of osteoporotic fracture in Swiss men and women. Osteoporos Int. 2009;20(7):1131–1140.18974918
176 Lippuner K, Johansson H, Kanis JA, Rizzoli R. FRAX® assessment of osteoporotic fracture probability in Switzerland. Osteoporos Int. 2010;21(3):381–389.19517155
177 Liu MY, Li CL, Pei Y, Xiao YJ, Zhang Y, Cheng XL. [Diagnostic values of self-assessment tool for Asians for osteoporosis in aged men]. Zhonghua Yi Xue Za Zhi. 2011;91(30):2112–2115.22093986
178 Lix LM, Quail J, Teare G, Acan B. Performance of comorbidity measures for predicting outcomes in population-based osteoporosis cohorts. Osteoporos Int. 2011;22(10):2633–2643.21305268
179 Li-Yu JT, Llamado LJ, Torralba TP. Validation of OSTA among Filipinos. Osteoporos Int. 2005;16(12):1789–1793.16027957
180 Looker AC, Mussolino ME. Serum 25-hydroxyvitamin D and hip fracture risk in older U.S. white adults. J Bone Miner Res. 2008;23(1):143–150.17907920
181 López AM, Pena MA, Hernández R, Val F, Martín B, Riancho JA. Fracture risk in patients with prostate cancer on androgen deprivation therapy. Osteoporos Int. 2005;16(6):707–711.15714259
182 López-Larramona G, Lucendo AJ, Tenías JM. Association between nutritional screening via the Controlling Nutritional Status index and bone mineral density in chronic liver disease of various etiologies. Hepatol Res. 2015;45(6):618–628.25059921
183 Luukinen H, Kakonen SM, Pettersson K, . Strong prediction of fractures among older adults by the ratio of carboxylated to total serum osteocalcin. J Bone Miner Res. 2000;15(12):2473–2478.11127212
184 Lynn HS, Lau EMC, Wong SYS, Hong AWL. An osteoporosis screening tool for Chinese men. Osteoporos Int. 2005;16(7):829–834.15536535
185 Lynn HS, Woo J, Leung PC, . An evaluation of osteoporosis screening tools for the osteoporotic fractures in men (MrOS) study. Osteoporos Int. 2008;19(7):1087–1092.18239959
186 Ma Z, Yang Y, Lin JS, . BFH-OST, a new predictive screening tool for identifying osteoporosis in postmenopausal han Chinese women. Clin Interv Aging. 2016;11:1051–1059.27536085
187 Madore GR, Sherman PJ, Lane JM. Parathyroid hormone. J Am Acad Orthop Surg. 2004;12(2):67–71.15089079
188 Magnus JH, Broussard DL. Can self-rated health identify us women and men with low bone mineral density? a cross-sectional population study. Gend Med. 2008;5(3):246–258.18727991
189 Majumdar SR, Josse RG, Lin M, Eurich DT. Does Sitagliptin Affect the Rate of Osteoporotic Fractures in Type 2 Diabetes? Population-Based Cohort Study. J Clin Endocrinol Metab. 2016;101(5):1963–1969.26930183
190 Marques ID, Araujo MJ, Graciolli FG, . Biopsy vs. peripheral computed tomography to assess bone disease in CKD patients on dialysis: differences and similarities. Osteoporos Int. 2017;28(5):1675–1683.28204954
191 Martineau P, Leslie WD, Johansson H, . In which patients does lumbar spine trabecular bone score (TBS) have the largest effect? Bone. 2018;113:161–168.29802962
192 Mazzantini M, Talarico R, Doveri M, . Incident comorbidity among patients with rheumatoid arthritis treated or not with low-dose glucocorticoids: a retrospective study. J Rheumatol. 2010;37(11):2232–2236.20843913
193 McCarthy MS. 3. The Challenges of Telehealth Coaching to Promote Bone Health in Deployed Soldiers. Nurs Outlook. 2015;63(1):102–102.
194 McDiarmid MA, Cloeren M, Gaitens JM, . Surveillance results and bone effects in the Gulf War depleted uranium-exposed cohort. J Toxicol Environ Health A. 2018;81(20):1083–1097.30373484
195 McDonald AM, Jones JA, Cardan RA, Saag KS, Mayhew DL, Fiveash JB. Combining Computed Tomography-Based Bone Density Assessment with FRAX Screening in Men with Prostate Cancer. J Clin Densitom. 2016;19(4):430–435.27241940
196 Meier C, Nguyen TV, Center JR, Seibel MJ, Eisman JA. Bone resorption and osteoporotic fractures in elderly men: the dubbo osteoporosis epidemiology study. J Bone Miner Res. 2005;20(4):579–587.15765176
197 Melcer T, Walker J, Bhatnagar V, Richard E, Sechriest VF, 2nd, Galarneau M. A Comparison of Four-Year Health Outcomes following Combat Amputation and Limb Salvage. PLoS One. 2017;12(1):e0170569.28122002
198 Melton LJ, Atkinson EJ, Achenbach SJ, . Potential extensions of the US FRAX algorithm. Journal of Osteoporosis. 2012;2012.
199 Michalski AS, Amin S, Cheung AM, . Hip load capacity cut-points for Astronaut Skeletal Health NASA Finite Element Strength Task Group Recommendations. NPJ Microgravity. 2019;5:6.30886891
200 Montagnani A, Gonnelli S, Cepollaro C, . Usefulness of bone quantitative ultrasound in management of osteoporosis in men. J Clin Densitom. 2001;4(3):231–237.11740065
201 Morse LR, Lazzari AA, Battaglino R, . Dual energy x-ray absorptiometry of the distal femur may be more reliable than the proximal tibia in spinal cord injury. Arch Phys Med Rehabil. 2009;90(5):827–831.19406303
202 Morse LR, Battaglino RA, Stolzmann KL, . Osteoporotic fractures and hospitalization risk in chronic spinal cord injury. Osteoporos Int. 2009;20(3):385–392.18581033
203 Mrgan M, Mohammed A, Gram J. Combined vertebral assessment and bone densitometry increases the prevalence and severity of osteoporosis in patients referred to DXA scanning. J Clin Densitom. 2013;16(4):549–553.23769657
204 Nassar K, Paternotte S, Kolta S, Fechtenbaum J, Roux C, Briot K. Added value of trabecular bone score over bone mineral density for identification of vertebral fractures in patients with areal bone mineral density in the non-osteoporotic range. Osteoporos Int. 2014;25(1):243–249.24081509
205 Nayak S, Greenspan SL. Cost-Effectiveness of Osteoporosis Screening Strategies for Men. J Bone Miner Res. 2016;31(6):1189–1199.26751984
206 Naylor KL, Garg AX, Zou G, . Comparison of fracture risk prediction among individuals with reduced and normal kidney function. Clin J Am Soc Nephrol. 2015;10(4):646–653.25655423
207 Nethander M, Pettersson-Kymmer U, Vandenput L, . BMD-Related Genetic Risk Scores Predict Site-Specific Fractures as Well as Trabecular and Cortical Bone Microstructure. J Clin Endocrinol Metab. 2020;105(4):e1344–1357.
208 Neubecker K, Adams-Huet B, Farukhi IM, Delapena RC, Gruntmanis U. Predictors of fracture risk and bone mineral density in men with prostate cancer on androgen deprivation therapy. J Osteoporos. 2011;2011:924595.21826255
209 Nguyen ND, Frost SA, Center JR, Eisman JA, Nguyen TV. Development of a nomogram for individualizing hip fracture risk in men and women. Osteoporos Int. 2007;18(8):1109–1117.17370100
210 Nicoll R, Black A, Bailey L, . Fracture risk calculation tool enhances dual-energy X-ray absorptiometry scan referral pathway in cirrhosis patients. Eur J Gastroenterol Hepatol. 2016;28(7):757–761.27254536
211 Ogunwale AN, Colon-Emeric CS, Sloane R, Adler RA, Lyles KW, Lee RH. Acetylcholinesterase Inhibitors Are Associated with Reduced Fracture Risk among Older Veterans with Dementia. J Bone Miner Res. 2020;35(3):440–445.31711264
212 Ogura-Tomomatsu H, Asano K, Tomomatsu K, . Predictors of osteoporosis and vertebral fractures in patients presenting with moderate-to-severe chronic obstructive lung disease. COPD: Journal of Chronic Obstructive Pulmonary Disease. 2012;9(4):332–337.22489911
213 Pang WY, Inderjeeth CA. FRAX without bone mineral density versus osteoporosis self-assessment screening tool as predictors of osteoporosis in primary screening of individuals aged 70 and older. J Am Geriatr Soc. 2014;62(3):442–446.24617899
214 Paniagua MA, Malphurs JE, Samos LF. BMI and low bone mass in an elderly male nursing home population. Clin Interv Aging. 2006;1(3):283–287.18046882
215 Park SH, Jia T, Qureshi AR, . Determinants and survival implications of low bone mineral density in end-stage renal disease patients. Journal of Nephrology. 2013;26(3):485–494.22976520
216 Park JS, Lee J, Park YS. Is It Possible to Increase the Clinical Effectiveness of the Fracture Risk Assessment Tool in Osteopenia Patients by Taking Into Account Bone Mineral Density Values? J Clin Densitom. 2016;19(3):340–345.26822485
217 Pasco JA, Lane SE, Brennan SL, . Fracture risk among older men: osteopenia and osteoporosis defined using cut-points derived from female versus male reference data. Osteoporos Int. 2014;25(3):857–862.24196721
218 Patil T, Hobson J. Risk of new-onset osteoporosis in single-center veteran population receiving direct oral anticoagulants versus warfarin. Thromb Res. 2021;200:56–63.33540293
219 Pepe J, Isidori AM, Falciano M, . The combination of FRAX and Ageing Male Symptoms scale better identifies treated HIV males at risk for major fracture. Clin Endocrinol (Oxf). 2012;77(5):672–678.22630782
220 Pérez-Castrillón JL, Sagredo MG, Conde R, del Pino-Montes J, de Luis D. OST Risk Index and Calcaneus Bone Densitometry in Osteoporosis Diagnosis. J Clin Densitom. 2007;10(4):404–407.17662631
221 Pham HM, Nguyen ND, Center JR, Eisman JA, Nguyen TV. Contribution of Quadriceps Weakness to Fragility Fracture: A Prospective Study. J Bone Miner Res. 2016;31(1):208–214.26174768
222 Pluskiewicz W, Adamczyk P, Franek E, . FRAX calculator and Garvan nomogram in male osteoporotic population. Aging Male. 2014;17(3):174–182.24456527
223 Poh LS, Taylor S, McAteer S. Refinement of an osteoporosis risk-assessment questionnaire for use in community pharmacy. Int J Pharm Pract. 2008;16(5):279–286.
224 Poór G, Atkinson EJ, O’Fallon WM, Melton ILJ. Predictors of hip fractures in elderly men. J Bone Miner Res. 1995;10(12):1900–1907.8619370
225 Pourmalek F, Goldenberg SL, Ho K, Skeldon SC, Patrick DM. Development and case-control validation of the Canadian men’s health foundation’s self risk-assessment tool: “you check”. Journal of Men’s Health. 2017;13(1):e9–e18.
226 Przedlacki J, Buczynska-Chyl J, Kozminski P, . The utility of FRAX(R) in predicting bone fractures in patients with chronic kidney disease on hemodialysis: a two-year prospective multicenter cohort study. Osteoporos Int. 2018;29(5):1105–1115.29411069
227 Pundole X, Murphy WA, Ebede CC, . Fracture risk prediction using FRAX in patients following hematopoietic stem cell transplantation. Arch Osteoporos. 2018;13(1):38.29619576
228 Ranstam J, Elffors L, Kanis JA. A mental-functional risk score for prediction of hip fracture. Age Ageing. 1996;25(6):439–442.9003879
229 Reber KC, Konig HH, Becker C, . Development of a risk assessment tool for osteoporotic fracture prevention: A claims data approach. Bone. 2018;110:170–176.29421456
230 Rendl S, Lapa C, Blumel C, Bundschuh RA, Schneider P. Decision making for osteoporotic treatment using FRAX or DVO risk algorithms in a clinical setting. J Musculoskelet Neuronal Interact. 2013;13(3):339–345.23989255
231 Richards JB, Leslie WD, Joseph L, . Changes to osteoporosis prevalence according to method of risk assessment. J Bone Miner Res. 2007;22(2):228–234.17129177
232 Riggs BL, Melton ILJ, Robb RA, . Population-based analysis of the relationship of whole bone strength indices and fall-related loads to age- and sex-specific patterns of hip and wrist fractures. J Bone Miner Res. 2006;21(2):315–323.16418788
233 Rodondi A, Chevalley T, Rizzoli R. Prevalence of vertebral fracture in oldest old nursing home residents. Osteoporos Int. 2012;23(11):2601–2606.22302103
234 Roig Vilaseca D, Valero Garcia C, Pilar Boncompte Vilanova M, Munoz Lopez J, Contreras Garcia C, Romera Baures M. [Sensitivity, specificity, positive and negative predictive values of the criteria for indicating a bone densitometry in the evaluation of medical techniques and research in Cataluna]. Reumatol Clin. 2011;7(3):161–166.21794807
235 Rotondi NK, Beaton DE, Elliot-Gibson V, . Comparison of CAROC and FRAX in Fragility Fracture Patients: Agreement, Clinical Utility, and Implications for Clinical Practice. J Rheumatol. 2016;43(8):1593–1599.27307534
236 Roumie CL. Statins reduce fracture risk in elderly male veterans. J Clin Outcomes Manag. 2005;12(11):555.
237 Routh RH, Rumancik S, Pathak RD, Burshell AL, Nauman EA. The relationship between bone mineral density and biomechanics in patients with osteoporosis and scoliosis. Osteoporos Int. 2005;16(12):1857–1863.15999291
238 Roux S, Cabana F, Carrier N, . The World Health Organization Fracture Risk Assessment Tool (FRAX) underestimates incident and recurrent fractures in consecutive patients with fragility fractures. J Clin Endocrinol Metab. 2014;99(7):2400–2408.24780062
239 Rubin KH, Moller S, Holmberg T, Bliddal M, Sondergaard J, Abrahamsen B. A New Fracture Risk Assessment Tool (FREM) Based on Public Health Registries. J Bone Miner Res. 2018;33(11):1967–1979.29924428
240 Rudman D, Drinka PJ, Wilson CR, . Relations of endogenous anabolic hormones and physical activity to bone mineral density and lean body mass in elderly men. Clin Endocrinol (Oxf). 1994;40(5):653–661.8013146
241 Salvig BE, Gulum AH, Walters SA, . Pharmacist Screening for Risk of Osteoporosis in Elderly Veterans. Consult Pharm. 2016;31(8):440–449.27535079
242 Samelson EJ, Broe KE, Xu H, . Cortical and trabecular bone microarchitecture as an independent predictor of incident fracture risk in older women and men in the Bone Microarchitecture International Consortium (BoMIC): a prospective study. Lancet Diabetes Endocrinol. 2019;7(1):34–43.30503163
243 Sandhu SK, Nguyen ND, Center JR, Pocock NA, Eisman JA, Nguyen TV. Prognosis of fracture: evaluation of predictive accuracy of the FRAX algorithm and Garvan nomogram. Osteoporos Int. 2010;21(5):863–871.19633880
244 Sanfelix-Genoves J, Peiro S, Sanfelix-Gimeno G, . Development and validation of a population-based prediction scale for osteoporotic fracture in the region of Valencia, Spain: the ESOSVAL-R study. BMC Public Health. 2010;10:153.20334639
245 Satyaraddi A, Shetty S, Kapoor N, . Performance of risk assessment tools for predicting osteoporosis in south Indian rural elderly men. Arch Osteoporos. 2017;12(1):35.28378274
246 Schmidt T, Schmidt C, Strahl A, . A System to Determine Risk of Osteoporosis in Patients With Autoimmune Hepatitis. Clinical gastroenterology and hepatology : the official clinical practice journal of the American Gastroenterological Association. 2019.
247 Schousboe JT, Gourlay M, Fink HA, . Cost-effectiveness of bone densitometry among Caucasian women and men without a prior fracture according to age and body weight. Osteoporos Int. 2013;24(1):163–177.22349916
248 Schousboe JT, Vo T, Taylor BC, . Prediction of Incident Major Osteoporotic and Hip Fractures by Trabecular Bone Score (TBS) and Prevalent Radiographic Vertebral Fracture in Older Men. J Bone Miner Res. 2016;31(3):690–697.26378772
249 Schwartz AV, Vittinghoff E, Bauer DC, . Association of BMD and FRAX score with risk of fracture in older adults with type 2 diabetes. JAMA. 2011;305(21):2184–2192.21632482
250 Schwartz AV, Sigurdsson S, Hue TF, . Vertebral bone marrow fat associated with lower trabecular BMD and prevalent vertebral fracture in older adults. J Clin Endocrinol Metab. 2013;98(6):2294–2300.23553860
251 Shahla A. Validity of bone mineral density and WHO fracture risk assessment thresholds in hip fractures. Arch Iran Med. 2011;14(5):352–354.21888461
252 Shan-Fu Y, Jia-Feng C, Yin-Chou C, . Beyond bone mineral density, FRAX-based tailor-made intervention thresholds for therapeutic decision in subjects on glucocorticoid: A nationwide osteoporosis survey. Medicine. 2017;96(5):1–7.
253 Sheer RL, Barron RL, Sudharshan L, Pasquale MK. Validated prediction of imminent risk of fracture for older adults. Am J Manag Care. 2020;26(3):e91–e97.32181621
254 Shojaei H, Soroush MR, Modirian E. Spinal cord injury-induced osteoporosis in veterans. Journal of Spinal Disorders and Techniques. 2006;19(2):114–117.16760785
255 Sieber PR, Rommel FM, Theodoran CG, Russinko PJ, Woodward CA, Schimke L. The role of distal third radius dual energy X-ray absorptiometry (DXA) and central DXA in evaluating for osteopenia and osteoporosis in men receiving androgen deprivation therapy for prostate cancer. J Clin Densitom. 2012;15(3):351–354.22542224
256 Siggeirsdottir K, Aspelund T, Johansson H, . The incidence of a first major osteoporotic fracture in Iceland and implications for FRAX. Osteoporos Int. 2014;25(10):2445–2451.24980183
257 Siminoski K, Leslie WD, Frame H, . Recommendations for Bone Mineral Density Reporting in Canada: A Shift to Absolute Fracture Risk Assessment. J Clin Densitom. 2007;10(2):120–123.17485028
258 Slemenda CW, Christian JC, Reed T, Reister TK, Williams CJ, Johnston CC, Jr. Long-term bone loss in men: effects of genetic and environmental factors. Ann Intern Med. 1992;117(4):286–291.1637023
259 Smith BJ, McElroy HJ, Laslett LL, . Osteoporosis screening in people with airways disease. Chron Respir Dis. 2005;2(1):5–12.16279743
260 Stanley HL, Schmitt BP, Poses RM, Deiss WP. Does hypogonadism contribute to the occurrence of a minimal trauma hip fracture in elderly men? J Am Geriatr Soc. 1991;39(8):766–771.2071807
261 Starr KP, Lyles K, Miller M, . Bone Mineral Density Responses to Obesity Reduction with Enhanced Protein: Short Term Results in Functionally Frail Older Adults (OR18-04-19). Curr Dev Nutr. 2019;3(Suppl 1).
262 Starup-Linde J, Lykkeboe S, Gregersen S, . Bone Structure and Predictors of Fracture in Type 1 and Type 2 Diabetes. J Clin Endocrinol Metab. 2016;101(3):928–936.26756117
263 Stefanovics EA, Potenza MN, Pietrzak RH. The physical and mental health burden of obesity in U.S. veterans: Results from the National Health and Resilience in Veterans Study. J Psychiatr Res. 2018;103:112–119.29807318
264 Stehman-Breen C. Bone mineral density measurements in dialysis patients. Semin Dial. 2001;14(3):228–229.
265 Stephens KI, Rubinsztain L, Payan J, Rentsch C, Rimland D, Tangpricha V. DUAL-ENERGY X-RAY ABSORPTIOMETRY AND CALCULATED FRAX RISK SCORES MAY UNDERESTIMATE OSTEOPOROTIC FRACTURE RISK IN VITAMIN D-DEFICIENT VETERANS WITH HIV INFECTION. Endocr Pract. 2016;22(4):440–446.26684149
266 Stockbrügger RW, Schoon EJ, Bollani S, . Discordance between the degree of osteopenia and the prevalence of spontaneous vertebral fractures in Crohn’s disease. Aliment Pharmacol Ther. 2002;16(8):1519–1527.12182752
267 Su Y, Leung J, Hans D, Aubry-Rozier B, Kwok T. Added clinical use of trabecular bone score to BMD for major osteoporotic fracture prediction in older Chinese people: the Mr. OS and Ms. OS cohort study in Hong Kong. Osteoporos Int. 2017;28(1):151–160.27725999
268 Su Y, Leung J, Hans D, Lamy O, Kwok T. The added value of trabecular bone score to FRAX(R) to predict major osteoporotic fractures for clinical use in Chinese older people: the Mr. OS and Ms. OS cohort study in Hong Kong. Osteoporos Int. 2017;28(1):111–117.27565645
269 Su Y, Leung J, Kwok T. The role of previous falls in major osteoporotic fracture prediction in conjunction with FRAX in older Chinese men and women: the Mr. OS and Ms. OS cohort study in Hong Kong. Osteoporos Int. 2018;29(6):1469.29651509
270 Su Y, Woo JW, Kwok TCY. The Added Value of SARC-F to Prescreening Using FRAX for Hip Fracture Prevention in Older Community Adults. J Am Med Dir Assoc. 2019;20(1):83–89.30314676
271 Su Y, Kwok TCY, Cummings SR, Yip BHK, Cawthon PM. Can Classification and Regression Tree Analysis Help Identify Clinically Meaningful Risk Groups for Hip Fracture Prediction in Older American Men (The MrOS Cohort Study)? JBMR Plus. 2019;3(10):e10207.31687643
272 Sutton SS, Magagnoli J, Hardin JW, . Association of tenofovir disoproxil fumarate exposure with chronic kidney disease and osteoporotic fracture in US veterans with HIV. Curr Med Res Opin. 2020;36(10):1635–1642.32856940
273 Szulc P, Munoz F, Duboeuf F, Marchand F, Delmas PD. Bone mineral density predicts osteoporotic fractures in elderly men: The MINOS study. Osteoporos Int. 2005;16(10):1184–1192.16096713
274 Tang YJ, Sheu WHH, Liu PH, Lee WJ, Chen YT. Positive associations of bone mineral density with body mass index, physical activity, and blood triglyceride level in men over 70 years old: A TCVGHAGE study. J Bone Miner Metab. 2007;25(1):54–59.17187194
275 Taylor EN, Feskanich D, Paik JM, Curhan GC. Nephrolithiasis and Risk of Incident Bone Fracture. J Urol. 2016;195(5):1482–1486.26707509
276 Timmer MH, Samson MM, Monninkhof EM, De Ree B, Verhaar HJ. Predicting osteoporosis in patients with a low-energy fracture. Arch Gerontol Geriatr. 2009;49(1):e32–35.18835048
277 Torstensson M, Hansen AH, Leth-Moller K, . Danish register-based study on the association between specific cardiovascular drugs and fragility fractures. BMJ Open. 2015;5(12):e009522.
278 Tortora R, Imperatore N, Capone P, . FRAX Score Can Be Used to Avoid Superfluous DXA Scans in Detecting Osteoporosis in Celiac Disease: Accuracy of the FRAX Score in Celiac Patients. J Clin Densitom. 2018;21(3):315–321.28625602
279 Travers-Gustafson D, Stegman MR, Heaney RP, Recker RR. Ultrasound, densitometry, and extraskeletal appendicular fracture risk factors: A cross-sectional report on the Saunders County Bone Quality Study. Calcif Tissue Int. 1995;57(4):267–271.8673863
280 Tugcu I, Safaz I, Yilmaz B, Goktepe AS, Taskaynatan MA, Yazicioglu K. Muscle strength and bone mineral density in mine victims with transtibial amputation. Prosthet Orthot Int. 2009;33(4):299–306.19961291
281 Välimäki VV, Alfthan H, Lehmuskallio E, . Risk factors for clinical stress fractures in male military recruits: A prospective cohort study. Bone. 2005;37(2):267–273.15964254
282 Välimäki VV, Löyttyniemi E, Välimäki MJ. Quantitative ultrasound variables of the heel in Finnish men aged 18-20 yr: Predictors, relationship to bone mineral content, and changes during military service. Osteoporos Int. 2006;17(12):1763–1771.16944074
283 van der Veer E, Arends S, van der Hoek S, . Predictors of new fragility fractures after diagnosis of indolent systemic mastocytosis. J Allergy Clin Immunol. 2014;134(6):1413–1421.24985401
284 van Staa TP, Leufkens HG, Cooper C. Utility of medical and drug history in fracture risk prediction among men and women. Bone. 2002;31(4):508–514.12398948
285 van Varsseveld NC, Sohl E, Drent ML, Lips P. Gender-Specific Associations of Serum Insulin-Like Growth Factor-1 With Bone Health and Fractures in Older Persons. J Clin Endocrinol Metab. 2015;100(11):4272–4281.26323023
286 Vanderschueren D, Boonen S, Bouillon R. Osteoporosis and osteoporotic fractures in men: A clinical perspective. Bailliere’s Best Practice and Research in Clinical Endocrinology and Metabolism. 2000;14(2):299–315.11035908
287 Verdijk NA, Romeijnders AC, Ruskus JJ, van der Sluijs C, Pop VJ. Validation of the Dutch guidelines for dual X-ray absorptiometry measurement. Br J Gen Pract. 2009;59(561):256–260.19341554
288 Vokes TJ, Dixon LB, Favus MJ. Clinical utility of dual-energy vertebral assessment (DVA). Osteoporos Int. 2003;14(11):871–878.13680099
289 Vokes T, Lauderdale D, Ma SL, Chinander M, Childs K, Giger M. Radiographic texture analysis of densitometric calcaneal images: Relationship to clinical characteristics and to bone fragility. J Bone Miner Res. 2010;25(1):56–63.19594292
290 Waljee AK, Wiitala WL, Govani S, . Corticosteroid Use and Complications in a US Inflammatory Bowel Disease Cohort. PLoS One. 2016;11(6):e0158017.27336296
291 Wang X, Sanyal A, Cawthon PM, . Prediction of new clinical vertebral fractures in elderly men using finite element analysis of CT scans. J Bone Miner Res. 2012;27(4):808–816.22190331
292 Ward IM, Mortensen EM, Battafarano DF, Frei CR, Mansi I. Association of Statins and Risk of Fractures in a Military Health System: A Propensity Score–Matched Analysis. Ann Pharmacother. 2014;48(11):1406–1414.25070396
293 Wehrli FW, Hopkins JA, Hwang SN, Hee Kwon S, Snyder PJ, Haddad JG. Cross-sectional study of osteopenia with quantitative MRI imaging and bone densitometry. Radiology. 2000;217(2):527–538.11058656
294 Westfall G, Littlefield R, Heaton A, Martin S. Methodology for identifying patients at high risk for osteoporotic fracture. Clin Ther. 2001;23(9):1570–1588.11589269
295 Wilcox A, Carnes ML, Moon TD, . Androgen deprivation in veterans with prostate cancer: implications for skeletal health. Ann Pharmacother. 2006;40(12):2107–2114.17132807
296 Wildberger L, Boyadzhieva V, Hans D, Stoilov N, Rashkov R, Aubry-Rozier B. Impact of lumbar syndesmophyte on bone health as assessed by bone density (BMD) and bone texture (TBS) in men with axial spondyloarthritis. Joint Bone Spine. 2017;84(4):463–466.27450198
297 Wilson C. Bone: Bisphosphonate therapy after cardiac transplant reduces fracture risk. Nature Reviews Endocrinology. 2009;5(7):356.
298 Woo A, Hittell J, Beardsley C, Noh C, Stoukides CA, Kaul AF. An ongoing six-year innovative osteoporosis disease management program: challenges and success in an IPA physician group environment. Dis Manag. 2004;7(3):216–225.15669581
299 Wu Q, Nasoz F, Jung J, Bhattarai B, Han MV. Machine Learning Approaches for Fracture Risk Assessment: A Comparative Analysis of Genomic and Phenotypic Data in 5130 Older Men. Calcif Tissue Int. 2020;107(4):353–361.32728911
300 Xu G, Yamamoto N, Hayashi K, . The accuracy of different FRAX tools in predicting fracture risk in Japan: A comparison study. J Orthop Surg (Hong Kong). 2020;28(2):2309499020917276.32336240
301 Yang Y, Li D, Fei Q, . Self-assessment Tool to Identify Primary Osteoporosis in Chinese Elderly Males. International Journal of Gerontology. 2015;9(2):71–76.
302 Yang S, Leslie WD, Walld R, . Objectively-Verified Parental Non-Hip Major Osteoporotic Fractures and Offspring Osteoporotic Fracture Risk: A Population-Based Familial Linkage Study. J Bone Miner Res. 2017;32(4):716–721.27859612
303 Yaturu S, Humphrey S, Landry C, Jain SK. Decreased bone mineral density in men with metabolic syndrome alone and with type 2 diabetes. Med Sci Monit. 2009;15(1):CR5-CR9.19114969
304 Yazdanpanah N, Zillikens MC, Rivadeneira F, . Effect of dietary B vitamins on BMD and risk of fracture in elderly men and women: The Rotterdam Study. Bone. 2007;41(6):987–994.17936100
305 Ye C, Li J, Hao S, . Identification of elders at higher risk for fall with statewide electronic health records and a machine learning algorithm. Int J Med Inform. 2020;137:104105.32193089
306 Yeh SS, Phanumas D, Hafner A, Schuster MW. Risk Factors for Osteoporosis in a Subgroup of Elderly Men in a Veterans Administration Nursing Home. J Investig Med. 2002;50(6):452–457.
307 Yoon J, Kwon SR, Lim MJ, . A comparison of three different guidelines for osteoporosis treatment in patients with rheumatoid arthritis in Korea. Korean J Intern Med. 2010;25(4):436–446.21179283
308 Yu SF, Chen JF, Chen YC, . Beyond bone mineral density, FRAX-based tailor-made intervention thresholds for therapeutic decision in subjects on glucocorticoid: A nationwide osteoporosis survey. Medicine (Baltimore). 2017;96(5):e5959.28151883
309 Zhang M, Li Y, Liu Y, Pan X, Liang B, Liu Z. A study of bone mineral density and prevalence of osteoporosis in Chinese people of Han nationality from Changchun. Archives of Osteoporosis. 2012;7(1–2):31–36.23225279
310 Zhang HM, Liu HL, Wang X, . Clinical value of self-assessment risk of osteoporosis in Chinese. Open Med (Wars). 2016;11(1):190–195.28352792
311 Zhang X, Lin J, Yang Y, . Comparison of three tools for predicting primary osteoporosis in an elderly male population in Beijing: a cross-sectional study. Clin Interv Aging. 2018;13:201–209.29440880
312 Zhang Y, Hao Q, Ge M, Dong B. Association of sarcopenia and fractures in community-dwelling older adults: a systematic review and meta-analysis of cohort studies. Osteoporos Int. 2018;29(6):1253–1262.29500527
313 Zhong BY, He SC, Zhu HD, . Risk Prediction of New Adjacent Vertebral Fractures After PVP for Patients with Vertebral Compression Fractures: Development of a Prediction Model. Cardiovasc Intervent Radiol. 2017;40(2):277–284.27812782
314 Zhou H, Mori S, Ishizaki T, . Genetic risk score based on the lifetime prevalence of femoral fracture in 924 consecutive autopsies of Japanese males. J Bone Miner Metab. 2016;34(6):685–691.26462479
315 Zhu K, Devine A, Lewis JR, Dhaliwal SS, Prince RL. “‘Timed up and go’ test and bone mineral density measurement for fracture prediction. Arch Intern Med. 2011;171(18):1655–1661.21987195