# APPENDIX C KQ 3 STUDY CHARACTERISTICS TABLE

Please refer to the main report’s reference list for citations in this Appendix.