# APPENDIX B KQ 1 AND KQ 2 STUDY CHARACTERISTICS TABLE

Please refer to the main report’s reference list for citations in this Appendix.