# APPENDIX A SEARCH STRATEGIES

## KEY QUESTION 1

### Database: MEDLINE (via PubMed)

#### Search date: 6/28/2019

#1 | “Osteoporosis”[Mesh:NoExp] OR “Bone Density”[Mesh] OR “Bone Diseases, Metabolic”[Mesh:NoExp] OR “Osteoporotic Fractures”[Mesh] OR osteoporosis[tiab] OR osteoporoses[tiab] OR osteoporotic[tiab] OR osteopenia[tiab] OR osteopenias[tiab] OR osteopenic[tiab] OR “bone loss”[tiab] OR “bone losses”[tiab] OR “bone mineral density”[tiab] OR “bone mineral densities”[tiab] OR BMD[tiab] OR “bone mineral content”[tiab] OR “bone mineral contents”[tiab] OR “bone density”[tiab] OR “bone densities”[tiab] OR “bone demineralization”[tiab] OR “bone dimineralizations”[tiab] OR “bone decalcification”[tiab] OR “bone decalcifications”[tiab] OR “fragility fracture”[tiab] OR “fragility fractures”[tiab] OR “bone fragility”[tiab] OR “bone fragilities”[tiab] | 144,180
#2 | “Male”[Mesh] OR male[tiab] OR males[tiab] OR man[tiab] OR men[tiab] OR gender[tiab] OR “sex characteristic”[tiab] OR “sex characteristics”[tiab] OR “sex difference”[tiab] OR “sex differences”[tiab] OR “biological sex”[tiab] | 8,591,644
#3 | “Risk assessment”[Mesh] OR “risk assessment”[tiab] OR “risk assessments”[tiab] OR “risk estimation”[tiab] OR “risk estimations”[tiab] OR “risk evaluation”[tiab] OR “risk evaluations”[tiab] OR “risk tool”[tiab] OR “risk tools”[tiab] OR “risk prediction”[tiab] OR “risk predictions”[tiab] OR “risk calculator”[tiab] OR “risk calculators”[tiab] OR “risk score”[tiab] OR “risk scores” OR “risk scoring”[tiab] OR “fracture prediction”[tiab] OR “fracture predictions”[tiab] OR “fracture assessment”[tiab] OR “fracture assessments”[tiab] OR “fracture estimation”[tiab] OR “fracture estimations”[tiab] OR FRAX[tiab] OR OST[tiab] OR “Self-Assessment Tool”[tiab] OR ORAI[tiab] OR OSTA[tiab] OR “Osteoporosis Self-assessment Tool for Asians”[tiab] OR OSIRIS[tiab] OR “Osteoporosis Index of Risk”[tiab] OR SOFSURF[tiab] OR “Study of Osteoporotic Fractures Simple Useful Risk”[tiab] OR “Male Osteoporosis Screening Tool”[tiab] OR OPRA[tiab] OR FRISK[tiab] OR FRC[tiab] OR MSCORE[tiab] OR MORES[tiab] OR “Garvan Fracture Risk”[tiab] OR QFracture[tiab] OR “Q Fracture”[tiab] | 309,022
#4 | #1 AND #2 AND #3 | 2,555
#5 | “randomized controlled trial”[ptyp] OR “controlled clinical trial”[ptyp] OR randomized[tiab] OR randomised[tiab] OR randomization[tiab] OR randomisation[tiab] OR placebo[tiab] OR randomly[tiab] OR trial[tiab] OR groups[tiab] OR “Comparative Study”[ptyp] OR “clinical trial”[pt] OR “clinical trial”[tiab] OR “clinical trials”[tiab] OR “evaluation studies”[ptyp] OR “evaluation studies as topic”[MeSH] OR “evaluation study”[tiab] OR “evaluation studies”[tiab] OR “intervention study”[tiab] OR “intervention studies”[tiab] OR “cohort studies”[MeSH] OR cohort[tiab] OR “longitudinal studies”[MeSH] OR longitudinal[tiab] OR longitudinally[tiab] OR prospective[tiab] OR prospectively[tiab] OR “follow up”[tiab] OR “comparative study”[pt] OR “comparative studies”[tiab] OR nonrandom[tiab] OR “non-random”[tiab] OR nonrandomized[tiab] OR “non-randomized”[tiab] OR nonrandomised[tiab] OR “non-randomised”[tiab] OR quasi-experiment*[tiab] OR quasiexperiment*[tiab] OR quasirandom*[tiab] OR quasirandom*[tiab] OR quasi-control*[tiab] OR quasicontrol*[tiab] OR ((controlled[tiab]) AND (trial[tiab] OR study[tiab])) | 7,175,132
#6 | “pre-post”[tiab] OR “posttest”[tiab] OR “post-test”[tiab] OR pretest[tiab] OR “pre-test”[tiab] OR “repeated measure”[tiab] OR “repeated measures”[tiab] | 66,760
#7 | (before[tiab] AND after[tiab]) OR (before[tiab] AND during[tiab]) | 108
#8 | “time series”[tiab] AND interrupt*[tiab] | 2,671
#9 | (“time points”[tiab]) AND (multiple[tiab] OR one[tiab] OR two[tiab] OR three[tiab] OR four[tiab] OR five[tiab] OR six[tiab] OR seven[tiab] OR eight[tiab] OR nine[tiab] OR ten[tiab] OR month[tiab] OR monthly[tiab] OR day[tiab] OR daily[tiab] OR week[tiab] OR weekly[tiab] OR hour[tiab] OR hourly[tiab]) | 59,141
#10 | #5 OR #6 OR #7 OR #8 OR #9 | 7,214,155
#11 | #4 AND #10 | 1,618
#12 | #11 NOT (Editorial[ptyp] OR Letter[ptyp] OR Case Reports[ptyp] OR Comment[ptyp]) | 1,561
#13 | #12 NOT (animals[mh] NOT humans[mh]) | 1,545

### Database: MEDLINE (via PubMed) Search Update

#### Search date: 2/23/2021

#1 | “Osteoporosis”[Mesh:NoExp] OR “Bone Density”[Mesh] OR “Bone Diseases, Metabolic”[Mesh:NoExp] OR “Osteoporotic Fractures”[Mesh] OR osteoporosis[tiab] OR osteoporoses[tiab] OR osteoporotic[tiab] OR osteopenia[tiab] OR osteopenias[tiab] OR osteopenic[tiab] OR “bone loss”[tiab] OR “bone losses”[tiab] OR “bone mineral density”[tiab] OR “bone mineral densities”[tiab] OR BMD[tiab] OR “bone mineral content”[tiab] OR “bone mineral contents”[tiab] OR “bone density”[tiab] OR “bone densities”[tiab] OR “bone demineralization”[tiab] OR “bone dimineralizations”[tiab] OR “bone decalcification”[tiab] OR “bone decalcifications”[tiab] OR “fragility fracture”[tiab] OR “fragility fractures”[tiab] OR “bone fragility”[tiab] OR “bone fragilities”[tiab] | 158,583
#2 | “Male”[Mesh] OR male[tiab] OR males[tiab] OR man[tiab] OR men[tiab] OR gender[tiab] OR “sex characteristic”[tiab] OR “sex characteristics”[tiab] OR “sex difference”[tiab] OR “sex differences”[tiab] OR “biological sex”[tiab] | 9,255,526
#3 | “Risk assessment”[Mesh] OR “risk assessment”[tiab] OR “risk assessments”[tiab] OR “risk estimation”[tiab] OR “risk estimations”[tiab] OR “risk evaluation”[tiab] OR “risk evaluations”[tiab] OR “risk tool”[tiab] OR “risk tools”[tiab] OR “risk prediction”[tiab] OR “risk predictions”[tiab] OR “risk calculator”[tiab] OR “risk calculators”[tiab] OR “risk score”[tiab] OR “risk scores” OR “risk scoring”[tiab] OR “fracture prediction”[tiab] OR “fracture predictions”[tiab] OR “fracture assessment”[tiab] OR “fracture assessments”[tiab] OR “fracture estimation”[tiab] OR “fracture estimations”[tiab] OR FRAX[tiab] OR OST[tiab] OR “Self-Assessment Tool”[tiab] OR ORAI[tiab] OR OSTA[tiab] OR “Osteoporosis Self-assessment Tool for Asians”[tiab] OR OSIRIS[tiab] OR “Osteoporosis Index of Risk”[tiab] OR SOFSURF[tiab] OR “Study of Osteoporotic Fractures Simple Useful Risk”[tiab] OR “Male Osteoporosis Screening Tool”[tiab] OR OPRA[tiab] OR FRISK[tiab] OR FRC[tiab] OR MSCORE[tiab] OR MORES[tiab] OR “Garvan Fracture Risk”[tiab] OR QFracture[tiab] OR “Q Fracture”[tiab] | 358,174
#4 | #1 AND #2 AND #3 | 2,991
#5 | “randomized controlled trial”[ptyp] OR “controlled clinical trial”[ptyp] OR randomized[tiab] OR randomised[tiab] OR randomization[tiab] OR randomisation[tiab] OR placebo[tiab] OR randomly[tiab] OR trial[tiab] OR groups[tiab] OR “Comparative Study”[ptyp] OR “clinical trial”[pt] OR “clinical trial”[tiab] OR “clinical trials”[tiab] OR “evaluation studies”[ptyp] OR “evaluation studies as topic”[MeSH] OR “evaluation study”[tiab] OR “evaluation studies”[tiab] OR “intervention study”[tiab] OR “intervention studies”[tiab] OR “cohort studies”[MeSH] OR cohort[tiab] OR “longitudinal studies”[MeSH] OR longitudinal[tiab] OR longitudinally[tiab] OR prospective[tiab] OR prospectively[tiab] OR “follow up”[tiab] OR “comparative study”[pt] OR “comparative studies”[tiab] OR nonrandom[tiab] OR “non-random”[tiab] OR nonrandomized[tiab] OR “non-randomized”[tiab] OR nonrandomised[tiab] OR “non-randomised”[tiab] OR quasi-experiment*[tiab] OR quasiexperiment*[tiab] OR quasirandom*[tiab] OR quasi-random*[tiab] OR quasi-control*[tiab] OR quasicontrol*[tiab] OR ((controlled[tiab]) AND (trial[tiab] OR study[tiab])) | 7,790,112
#6 | “pre-post”[tiab] OR “posttest”[tiab] OR “post-test”[tiab] OR pretest[tiab] OR “pre-test”[tiab] OR “repeated measure”[tiab] OR “repeated measures”[tiab] | 79,063
#7 | (before[tiab] AND after[tiab]) OR (before[tiab] AND during[tiab]) | 68
#8 | “time series”[tiab] AND interrupt*[tiab] | 3,718
#9 | (“time points”[tiab]) AND (multiple[tiab] OR one[tiab] OR two[tiab] OR three[tiab] OR four[tiab] OR five[tiab] OR six[tiab] OR seven[tiab] OR eight[tiab] OR nine[tiab] OR ten[tiab] OR month[tiab] OR monthly[tiab] OR day[tiab] OR daily[tiab] OR week[tiab] OR weekly[tiab] OR hour[tiab] OR hourly[tiab]) | 68,877
#10 | #5 OR #6 OR #7 OR #8 OR #9 | 7,836,590
#11 | #4 AND #10 | 1,916
#12 | #11 NOT (Editorial[ptyp] OR Letter[ptyp] OR Case Reports[ptyp] OR Comment[ptyp]) | 1,852
#13 | #12 NOT (animals[mh] NOT humans[mh]) | 1,836
#14 | #13 AND (“2019/06/01”[mhda] : “3000”[mhda] | 350

### Database: EMBASE (via Elsevier)

#### Search date: 6/28/2019

#1 | ‘bone demineralization’/de OR ‘osteoporosis’/de OR ‘corticosteroid induced osteoporosis’/de OR ‘idiopathic osteoporosis’/de OR ‘posttraumatic osteoporosis’/de OR ‘primary osteoporosis’/de OR ‘secondary osteoporosis’/de OR ‘senile osteoporosis’/de OR ‘metabolic bone disease’/de OR ‘bone density’/exp OR ‘fragility fracture’/exp OR steoporosis:ti,ab OR osteoporoses:ti,ab OR osteoporotic:ti,ab OR osteopenia:ti,ab OR osteopenias:ti,ab OR osteopenic:ti,ab OR ‘bone loss’:ti,ab OR ‘bone losses’:ti,ab OR ‘bone mineral density’:ti,ab OR ‘bone mineral densities’:ti,ab OR BMD:ti,ab OR ‘bone mineral content’:ti,ab OR ‘bone mineral contents’:ti,ab OR ‘bone density’:ti,ab OR ‘bone densities’:ti,ab OR ‘bone demineralization’:ti,ab OR ‘bone dimineralizations’:ti,ab OR ‘bone decalcification’:ti,ab OR ‘bone decalcifications’:ti,ab OR ‘fragility fracture’:ti,ab OR ‘fragility fractures’:ti,ab OR ‘bone fragility’:ti,ab OR ‘bone fragilities’:ti,ab | 218,310
#2 | ‘male’/exp OR male:ti,ab OR males:ti,ab OR man:ti,ab OR men:ti,ab OR gender:ti,ab OR ‘sex characteristic’:ti,ab OR ‘sex characteristics’:ti,ab OR ‘sex difference’:ti,ab OR ‘sex differences’:ti,ab OR ‘biological sex’:ti,ab | 9,238,793
#3 | ‘risk assessment’/exp OR ‘risk assessment’:ti,ab OR ‘risk assessments’:ti,ab OR ‘risk estimation’:ti,ab OR ‘risk estimations’:ti,ab OR ‘risk evaluation’:ti,ab OR ‘risk evaluations’:ti,ab OR ‘risk tool’:ti,ab OR ‘risk tools’:ti,ab OR ‘risk prediction’:ti,ab OR ‘risk predictions’:ti,ab OR ‘risk calculator’:ti,ab OR ‘risk calculators’:ti,ab OR ‘risk score’:ti,ab OR ‘risk scores’ OR ‘risk scoring’:ti,ab OR ‘fracture prediction’:ti,ab OR ‘fracture predictions’:ti,ab OR ‘fracture assessment’:ti,ab OR ‘fracture assessments’:ti,ab OR ‘fracture estimation’:ti,ab OR ‘fracture estimations’:ti,ab OR FRAX:ti,ab OR OST:ti,ab OR ‘Self Assessment Tool’:ti,ab OR ORAI:ti,ab OR OSTA:ti,ab OR ‘Osteoporosis Self-assessment Tool for Asians’:ti,ab OR OSIRIS:ti,ab OR ‘Osteoporosis Index of Risk’:ti,ab OR SOFSURF:ti,ab OR ‘Study of Osteoporotic Fractures Simple Useful Risk’:ti,ab OR ‘Male Osteoporosis Screening Tool’:ti,ab OR OPRA:ti,ab OR FRISK:ti,ab OR FRC:ti,ab OR MSCORE:ti,ab OR MORES:ti,ab OR ‘Garvan Fracture Risk’:ti,ab OR QFracture:ti,ab OR ‘Q Fracture’:ti,ab | 577,199
#4 | #1 AND #2 AND #3 | 5,452
#5 | ‘randomized controlled trial’/exp OR ‘crossover procedure’/exp OR ‘double blind procedure’/exp OR ‘single blind procedure’/exp OR randomization:ti,ab OR randomisation:ti,ab OR randomized:ti,ab OR randomised:ti,ab OR randomly:ti,ab OR crossover:ti,ab OR ‘cross over’:ti,ab OR placebo:ti,ab OR ‘double blind’:ti,ab OR ‘double blinded’:ti,ab OR ‘single blind’:ti,ab OR ‘single blinded’:ti,ab OR ‘clinical study’/exp OR ‘clinical trial’:ti,ab OR ‘clinical trials’:ti,ab OR ‘controlled study’/exp OR ‘evaluation study’/exp OR ‘evaluation study’:ti,ab OR ‘evaluation studies’:ti,ab OR ‘intervention study’/exp OR ‘intervention study’:ti,ab OR ‘intervention studies’:ti,ab OR ‘case control study’/exp OR ‘case control’:ti,ab OR ‘cohort analysis’/exp OR cohort:ti,ab OR cohorts:ti,ab OR longitudinal:ti,ab OR longitudinally:ti,ab OR prospective:ti,ab OR prospectively:ti,ab OR retrospective:ti,ab OR ‘follow up’/exp OR ‘follow up’:ti,ab OR ‘comparative effectiveness’/exp OR ‘comparative study’/exp OR ‘comparative study’:ti,ab OR ‘comparative studies’:ti,ab | 15,450,373
#6 | pre-post:ti,ab OR prepost:ti,ab OR post-test:ti,ab OR posttest:ti,ab OR pretest:ti,ab OR pre-test:ti,ab OR quasi-experiment:ti,ab OR quasiexperiment:ti,ab OR quasi-experimental:ti,ab OR quasiexperimental:ti,ab OR quasirandom:ti,ab OR quasi-random:ti,ab OR quasi-control:ti,ab OR quasicontrol:ti,ab OR ‘repeated measure’:ti,ab OR ‘repeated measures’:ti,ab | 110,907
#7 | (‘time series’:ti,ab AND interrupt:ti,ab) OR (before:ti,ab AND after:ti,ab) OR (before:ti,ab AND during:ti,ab) | 1,224,588
#8 | ‘time points’:ti,ab AND (multiple:ti,ab OR one:ti,ab OR two:ti,ab OR three:ti,ab OR four:ti,ab OR five:ti,ab OR six:ti,ab OR seven:ti,ab OR eight:ti,ab OR nine:ti,ab OR ten:ti,ab OR month:ti,ab OR monthly:ti,ab OR day:ti,ab OR days:ti,ab OR daily:ti,ab OR week:ti,ab OR weekly:ti,ab OR hour:ti,ab OR hourly:ti,ab) | 99,174
#9 | #5 OR #6 OR #7 OR #8 | 15,875,500
#10 | #4 AND #9 | 4,487
#11 | #10 NOT (‘case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR ‘letter’/exp OR ‘note’/exp OR [conference abstract]/lim) | 3,015
#12 | #11 AND [humans]/lim | 2,949

### Database: CINAHL (via EBSCO)

#### Search date: 6/28/2019

#1 | (MH “Osteoporosis”) OR (MH “Osteoporotic Fractures”) OR (MH “Bone Diseases, Metabolic”) OR (MH “Bone Density”) OR TI (osteoporosis OR osteoporoses OR osteoporotic OR osteopenia OR osteopenias OR osteopenic OR “bone loss” OR “bone losses” OR “bone mineral density” OR “bone mineral densities” OR BMD OR “bone mineral content” OR “bone mineral contents” OR “bone density” OR “bone densities” OR “bone demineralization” OR “bone dimineralizations” OR “bone decalcification” OR “bone decalcifications” OR “fragility fracture” OR “fragility fractures” OR “bone fragility” OR “bone fragilities”) OR AB (osteoporosis OR osteoporoses OR osteoporotic OR osteopenia OR osteopenias OR osteopenic OR “bone loss” OR “bone losses” OR “bone mineral density” OR “bone mineral densities” OR BMD OR “bone mineral content” OR “bone mineral contents” OR “bone density” OR “bone densities” OR “bone demineralization” OR “bone dimineralizations” OR “bone decalcification” OR “bone decalcifications” OR “fragility fracture” OR “fragility fractures” OR “bone fragility” OR “bone fragilities”) | 41,298
#2 | (MH “Male”) OR TI (male OR males OR man OR men OR gender OR “sex characteristic” OR “sex characteristics” OR “sex difference” OR “sex differences” OR “biological sex”) OR AB (male OR males OR man OR men OR gender OR “sex characteristic” OR “sex characteristics” OR “sex difference” OR “sex differences” OR “biological sex”) | 1,580,410
#3 | (MH “Risk Assessment”) OR TI (“risk assessment” OR “risk assessments” OR “risk estimation” OR “risk estimations” OR “risk evaluation” OR “risk evaluations” OR “risk tool” OR “risk tools” OR “risk prediction” OR “risk predictions” OR “risk calculator” OR “risk calculators” OR “risk score” OR “risk scores” OR “risk scoring” OR “fracture prediction” OR “fracture predictions” OR “fracture assessment” OR “fracture assessments” OR “fracture estimation” OR “fracture estimations” OR FRAX OR OST OR “Self-Assessment Tool” OR ORAI OR OSTA OR “Osteoporosis Self-assessment Tool for Asians” OR OSIRIS OR “Osteoporosis Index of Risk” OR SOFSURF OR “Study of Osteoporotic Fractures Simple Useful Risk” OR “Male Osteoporosis Screening Tool” OR OPRA OR FRISK OR FRC OR MSCORE OR MORES OR “Garvan Fracture Risk” OR QFracture OR “Q Fracture”) OR AB (“risk assessment” OR “risk assessments” OR “risk estimation” OR “risk estimations” OR “risk evaluation” OR “risk evaluations” OR “risk tool” OR “risk tools” OR “risk prediction” OR “risk predictions” OR “risk calculator” OR “risk calculators” OR “risk score” OR “risk scores” OR “risk scoring” OR “fracture prediction” OR “fracture predictions” OR “fracture assessment” OR “fracture assessments” OR “fracture estimation” OR “fracture estimations” OR FRAX OR OST OR “Self-Assessment Tool” OR ORAI OR OSTA OR “Osteoporosis Self-assessment Tool for Asians” OR OSIRIS OR “Osteoporosis Index of Risk” OR SOFSURF OR “Study of Osteoporotic Fractures Simple Useful Risk” OR “Male Osteoporosis Screening Tool” OR OPRA OR FRISK OR FRC OR MSCORE OR MORES OR “Garvan Fracture Risk” OR QFracture OR “Q Fracture”) | 726,519
#4 | #1 AND #2 AND #3 | 3,113
#5 | (MH “Randomized Controlled Trials+”) OR TI (“randomized controlled trial” OR “controlled clinical trial” OR “randomized” OR “randomization” OR “randomised” OR “randomisation” OR “randomly” OR “trial” OR “groups” OR “comparative study” OR “nonrandom” OR “non-random” OR “nonrandomized” OR “non-randomized” OR “nonrandomised” OR “non-randomised” OR quasi-experiment* OR quasiexperiment* OR quasirandom* OR quasi-random* OR quasi-control* OR quasicontrol* OR (controlled AND (trial OR study)) OR “pre-post” OR “posttest” OR “post-test” OR “pretest” OR “pre-test” OR “repeated measure” OR “repeated measures” OR (“time series” AND “interrupt”) OR (“time points” AND (multiple OR one OR two OR three OR four OR five OR six OR seven OR eight OR nine OR ten OR month OR monthly OR day OR daily OR week OR weekly OR hour OR hourly)) OR (before AND after) OR (before AND during)) OR AB (“randomized controlled trial” OR “controlled clinical trial” OR “randomized” OR “randomization” OR “randomised” OR “randomisation” OR “randomly” OR “trial” OR “groups” OR “comparative study” OR “nonrandom” OR “non-random” OR “nonrandomized” OR “non-randomized” OR “nonrandomised” OR “non-randomised” OR quasi-experiment* OR quasiexperiment* OR quasirandom* OR quasi-random* OR quasi-control* OR quasicontrol* OR (controlled AND (trial OR study)) OR “pre-post” OR “posttest” OR “post-test” OR “pretest” OR “pre-test” “repeated measure” OR “repeated measures” OR (“time series” AND “interrupt”) OR (“time points” AND (multiple OR one OR two OR three OR four OR five OR six OR seven OR eight OR nine OR ten OR month OR monthly OR day OR daily OR week OR weekly OR hour OR hourly)) OR (before AND after) OR (before AND during)) | 748,301
#6 | #4 AND #5 | 1,030
#7 | #6 NOT PT ( Abstract OR Book OR Book Chapter OR Book Review OR Case Study OR Commentary OR Doctoral Dissertation OR Editorial OR Letter OR Masters Thesis OR Pamphlet OR Pamphlet Chapter OR Poetry ) NOT TI ( Editorial OR Letter OR “Case Report” OR Comment ) | 1,004

## KEY QUESTION 2

### Database: MEDLINE (via PubMed)

#### Search date: 6/28/2019

#1 | “Osteoporosis”[Mesh:NoExp] OR “Bone Density”[Mesh] OR “Bone Diseases, Metabolic”[Mesh:NoExp] OR “Osteoporotic Fractures”[Mesh] OR osteoporosis[tiab] OR osteoporoses[tiab] OR osteoporotic[tiab] OR osteopenia[tiab] OR osteopenias[tiab] OR osteopenic[tiab] OR “bone loss”[tiab] OR “bone losses”[tiab] OR “bone mineral density”[tiab] OR “bone mineral densities”[tiab] OR BMD[tiab] OR “bone mineral content”[tiab] OR “bone mineral contents”[tiab] OR “bone density”[tiab] OR “bone densities”[tiab] OR “bone demineralization”[tiab] OR “bone dimineralizations”[tiab] OR “bone decalcification”[tiab] OR “bone decalcifications”[tiab] OR “fragility fracture”[tiab] OR “fragility fractures”[tiab] OR “bone fragility”[tiab] OR “bone fragilities”[tiab] | 144,180
#2 | “Veterans”[Mesh] OR “Veterans Health”[Mesh] OR “United States Department of Veterans Affairs”[Mesh] OR “Veterans Disability Claims”[Mesh] OR “Hospitals, Veterans”[Mesh] OR “Warfare and Armed Conflicts”[Mesh:NoExp] OR “Armed Conflicts”[Mesh:NoExp] OR “Afghan Campaign 2001-”[Mesh] OR “Gulf War”[Mesh] OR “Iraq War, 2003-2011”[Mesh] OR “Korean War”[Mesh] OR “Vietnam Conflict”[Mesh] OR “World War I”[Mesh] OR Veteran[tiab] OR veterans[tiab] OR “Afghan Campaign”[tiab] OR “Afghan War”[tiab] OR “Operation Enduring Freedom”[tiab] OR “Operation New Dawn”[tiab] OR “Operation Iraqi Freedom”[tiab] OR “Gulf War”[tiab] OR “Iraq War”[tiab] OR “Operation Desert Shield”[tiab] OR “Operation Desert Storm”[tiab] OR “Vietnam War”[tiab] OR “Viet Nam War”[tiab] OR “Vietnam Conflict”[tiab] OR “Viet Nam Conflict”[tiab] OR “Vietnamese War”[tiab] OR “Vietnamese Conflict”[tiab] OR “Indochina War”[tiab] OR “Korean War”[tiab] OR “World War I”[tiab] OR “World War II”[tiab] OR WWI[tiab] OR WWII[tiab] | 51,169
#3 | #1 AND #2 | 217
#4 | “randomized controlled trial”[ptyp] OR “controlled clinical trial”[ptyp] OR randomized[tiab] OR randomised[tiab] OR randomization[tiab] OR randomisation[tiab] OR placebo[tiab] OR randomly[tiab] OR trial[tiab] OR groups[tiab] OR “Comparative Study”[ptyp] OR “clinical trial”[pt] OR “clinical trial”[tiab] OR “clinical trials”[tiab] OR “evaluation studies”[ptyp] OR “evaluation studies as topic”[MeSH] OR “evaluation study”[tiab] OR “evaluation studies”[tiab] OR “intervention study”[tiab] OR “intervention studies”[tiab] OR “cohort studies”[MeSH] OR cohort[tiab] OR “longitudinal studies”[MeSH] OR longitudinal[tiab] OR longitudinally[tiab] OR prospective[tiab] OR prospectively[tiab] OR “follow up”[tiab] OR “comparative study”[pt] OR “comparative studies”[tiab] OR nonrandom[tiab] OR “non-random”[tiab] OR nonrandomized[tiab] OR “non-randomized”[tiab] OR nonrandomised[tiab] OR “non-randomised”[tiab] OR quasi-experiment*[tiab] OR quasiexperiment*[tiab] OR quasirandom*[tiab] OR quasi-random*[tiab] OR quasi-control*[tiab] OR quasicontrol*[tiab] OR ((controlled[tiab]) AND (trial[tiab] OR study[tiab])) | 7,175,132
#5 | “pre-post”[tiab] OR “posttest”[tiab] OR “post-test”[tiab] OR pretest[tiab] OR “pre-test”[tiab] OR “repeated measure”[tiab] OR “repeated measures”[tiab] | 66,760
#6 | (before[tiab] AND after[tiab]) OR (before[tiab] AND during[tiab]) | 108
#7 | “time series”[tiab] AND interrupt*[tiab] | 2,671
#8 | (“time points”[tiab]) AND (multiple[tiab] OR one[tiab] OR two[tiab] OR three[tiab] OR four[tiab] OR five[tiab] OR six[tiab] OR seven[tiab] OR eight[tiab] OR nine[tiab] OR ten[tiab] OR month[tiab] OR monthly[tiab] OR day[tiab] OR daily[tiab] OR week[tiab] OR weekly[tiab] OR hour[tiab] OR hourly[tiab]) | 59,141
#9 | #4 OR #5 OR #6 OR #7 OR #8 | 7,214,155
#10 | #3 AND #9 | 155
#11 | #10 NOT (Editorial[ptyp] OR Letter[ptyp] OR Case Reports[ptyp] OR Comment[ptyp]) | 154
#12 | #11 NOT (animals[mh] NOT humans[mh]) | 153

### MEDLINE (via PubMed) Search update

#### Search date: 2/23/2021

#1 | “Osteoporosis”[Mesh:NoExp] OR “Bone Density”[Mesh] OR “Bone Diseases, Metabolic”[Mesh:NoExp] OR “Osteoporotic Fractures”[Mesh] OR osteoporosis[tiab] OR osteoporoses[tiab] OR osteoporotic[tiab] OR osteopenia[tiab] OR osteopenias[tiab] OR osteopenic[tiab] OR “bone loss”[tiab] OR “bone losses”[tiab] OR “bone mineral density”[tiab] OR “bone mineral densities”[tiab] OR BMD[tiab] OR “bone mineral content”[tiab] OR “bone mineral contents”[tiab] OR “bone density”[tiab] OR “bone densities”[tiab] OR “bone demineralization”[tiab] OR “bone dimineralizations”[tiab] OR “bone decalcification”[tiab] OR “bone decalcifications”[tiab] OR “fragility fracture”[tiab] OR “fragility fractures”[tiab] OR “bone fragility”[tiab] OR “bone fragilities”[tiab] | 158,583
#2 | “Veterans”[Mesh] OR “Veterans Health”[Mesh] OR “United States Department of Veterans Affairs”[Mesh] OR “Veterans Disability Claims”[Mesh] OR “Hospitals, Veterans”[Mesh] OR “Warfare and Armed Conflicts”[Mesh:NoExp] OR “Armed Conflicts”[Mesh:NoExp] OR “Afghan Campaign 2001-”[Mesh] OR “Gulf War”[Mesh] OR “Iraq War, 2003-2011”[Mesh] OR “Korean War”[Mesh] OR “Vietnam Conflict”[Mesh] OR “World War I”[Mesh] OR Veteran[tiab] OR veterans[tiab] OR “Afghan Campaign”[tiab] OR “Afghan War”[tiab] OR “Operation Enduring Freedom”[tiab] OR “Operation New Dawn”[tiab] OR “Operation Iraqi Freedom”[tiab] OR “Gulf War”[tiab] OR “Iraq War”[tiab] OR “Operation Desert Shield”[tiab] OR “Operation Desert Storm”[tiab] OR “Vietnam War”[tiab] OR “Viet Nam War”[tiab] OR “Vietnam Conflict”[tiab] OR “Viet Nam Conflict”[tiab] OR “Vietnamese War”[tiab] OR “Vietnamese Conflict”[tiab] OR “Indochina War”[tiab] OR “Korean War”[tiab] OR “World War I”[tiab] OR “World War II”[tiab] OR WWI[tiab] OR WWII[tiab] | 57,162
#3 | #1 AND #2 | 253
#4 | “randomized controlled trial”[ptyp] OR “controlled clinical trial”[ptyp] OR randomized[tiab] OR randomised[tiab] OR randomization[tiab] OR randomisation[tiab] OR placebo[tiab] OR randomly[tiab] OR trial[tiab] OR groups[tiab] OR “Comparative Study”[ptyp] OR “clinical trial”[pt] OR “clinical trial”[tiab] OR “clinical trials”[tiab] OR “evaluation studies”[ptyp] OR “evaluation studies as topic”[MeSH] OR “evaluation study”[tiab] OR “evaluation studies”[tiab] OR “intervention study”[tiab] OR “intervention studies”[tiab] OR “cohort studies”[MeSH] OR cohort[tiab] OR “longitudinal studies”[MeSH] OR longitudinal[tiab] OR longitudinally[tiab] OR prospective[tiab] OR prospectively[tiab] OR “follow up”[tiab] OR “comparative study”[pt] OR “comparative studies”[tiab] OR nonrandom[tiab] OR “non-random”[tiab] OR nonrandomized[tiab] OR “non-randomized”[tiab] OR nonrandomised[tiab] OR “non-randomised”[tiab] OR quasi-experiment*[tiab] OR quasiexperiment*[tiab] OR quasirandom*[tiab] OR quasi-random*[tiab] OR quasi-control*[tiab] OR quasicontrol*[tiab] OR ((controlled[tiab]) AND (trial[tiab] OR study[tiab])) | 7,790,112
#5 | “pre-post”[tiab] OR “posttest”[tiab] OR “post-test”[tiab] OR pre-test[tiab] OR “pretest”[tiab] OR “repeated measure”[tiab] OR “repeated measures”[tiab] | 79,063
#6 | (before[tiab] AND after[tiab]) OR (before[tiab] AND during[tiab]) | 68
#7 | “time series”[tiab] AND interrupt*[tiab] | 3,718
#8 | (“time points”[tiab]) AND (multiple[tiab] OR one[tiab] OR two[tiab] OR three[tiab] OR four[tiab] OR five[tiab] OR six[tiab] OR seven[tiab] OR eight[tiab] OR nine[tiab] OR ten[tiab] OR month[tiab] OR monthly[tiab] OR day[tiab] OR daily[tiab] OR week[tiab] OR weekly[tiab] OR hour[tiab] OR hourly[tiab]) | 68,877
#9 | #4 OR #5 OR #6 OR #7 OR #8 | 7,836,590
#10 | #3 AND #9 | 175
#11 | #10 NOT (Editorial[ptyp] OR Letter[ptyp] OR Case Reports[ptyp] OR Comment[ptyp]) | 173
#12 | #11 NOT (animals[mh] NOT humans[mh]) | 172
#13 | #12 AND (“2019/06/01”[mhda] : “3000”[mhda] | 31

### Database: EMBASE (via Elsevier)

#### Search date: 6/28/2019

#1 | ‘bone demineralization’/de OR ‘osteoporosis’/de OR ‘corticosteroid induced osteoporosis’/de OR ‘idiopathic osteoporosis’/de OR ‘posttraumatic osteoporosis’/de OR ‘primary osteoporosis’/de OR ‘secondary osteoporosis’/de OR ‘senile osteoporosis’/de OR ‘metabolic bone disease’/de OR ‘bone density’/exp OR ‘fragility fracture’/exp OR steoporosis:ti,ab OR osteoporoses:ti,ab OR osteoporotic:ti,ab OR osteopenia:ti,ab OR osteopenias:ti,ab OR osteopenic:ti,ab OR ‘bone loss’:ti,ab OR ‘bone losses’:ti,ab OR ‘bone mineral density’:ti,ab OR ‘bone mineral densities’:ti,ab OR BMD:ti,ab OR ‘bone mineral content’:ti,ab OR ‘bone mineral contents’:ti,ab OR ‘bone density’:ti,ab OR ‘bone densities’:ti,ab OR ‘bone demineralization’:ti,ab OR ‘bone dimineralizations’:ti,ab OR ‘bone decalcification’:ti,ab OR ‘bone decalcifications’:ti,ab OR ‘fragility fracture’:ti,ab OR ‘fragility fractures’:ti,ab OR ‘bone fragility’:ti,ab OR ‘bone fragilities’:ti,ab | 218,238
#2 | ‘veteran’/exp OR ‘war’/exp OR ‘military phenomena’/de OR ‘military service’/exp OR ‘warfare’/exp OR ‘military deployment’/exp OR veteran:ti,ab OR veterans:ti,ab OR ‘Afghan Campaign’:ti,ab OR ‘Afghan War’:ti,ab OR ‘Operation Enduring Freedom’:ti,ab OR ‘Operation New Dawn’:ti,ab OR ‘Operation Iraqi Freedom’:ti,ab OR ‘Gulf War’:ti,ab OR ‘Iraq War’:ti,ab OR ‘Operation Desert Shield’:ti,ab OR ‘Operation Desert Storm’:ti,ab OR ‘Vietnam War’:ti,ab OR ‘Viet Nam War’:ti,ab OR ‘Vietnam Conflict’:ti,ab OR ‘Viet Nam Conflict’:ti,ab OR ‘Vietnamese War’:ti,ab OR ‘Vietnamese Conflict’:ti,ab OR ‘Indochina War’:ti,ab OR ‘Korean War’:ti,ab OR ‘World War I’:ti,ab OR ‘World War II’:ti,ab OR WWI:ti,ab OR WWII:ti,ab | 109,714
#3 | #1 AND #2 | 434
#4 | ‘randomized controlled trial’/exp OR ‘crossover procedure’/exp OR ‘double blind procedure’/exp OR ‘single blind procedure’/exp OR randomization:ti,ab OR randomisation:ti,ab OR randomized:ti,ab OR randomised:ti,ab OR randomly:ti,ab OR crossover:ti,ab OR ‘cross over’:ti,ab OR placebo:ti,ab OR ‘double blind’:ti,ab OR ‘double blinded’:ti,ab OR ‘single blind’:ti,ab OR ‘single blinded’:ti,ab OR ‘clinical study’/exp OR ‘clinical trial’:ti,ab OR ‘clinical trials’:ti,ab OR ‘controlled study’/exp OR ‘evaluation study’/exp OR ‘evaluation study’:ti,ab OR ‘evaluation studies’:ti,ab OR ‘intervention study’/exp OR ‘intervention study’:ti,ab OR ‘intervention studies’:ti,ab OR ‘case control study’/exp OR ‘case control’:ti,ab OR ‘cohort analysis’/exp OR cohort:ti,ab OR cohorts:ti,ab OR longitudinal:ti,ab OR longitudinally:ti,ab OR prospective:ti,ab OR prospectively:ti,ab OR retrospective:ti,ab OR ‘follow up’/exp OR ‘follow up’:ti,ab OR ‘comparative effectiveness’/exp OR ‘comparative study’/exp OR ‘comparative study’:ti,ab OR ‘comparative studies’:ti,ab | 15,450,373
#5 | pre-post:ti,ab OR prepost:ti,ab OR post-test:ti,ab OR posttest:ti,ab OR pretest:ti,ab OR pre-test:ti,ab OR quasi-experiment:ti,ab OR quasiexperiment:ti,ab OR quasi-experimental:ti,ab OR quasiexperimental:ti,ab OR quasirandom:ti,ab OR quasi-random:ti,ab OR quasi-control:ti,ab OR quasicontrol:ti,ab OR ‘repeated measure’:ti,ab OR ‘repeated measures’:ti,ab | 110,907
#6 | (‘time series’:ti,ab AND interrupt:ti,ab) OR (before:ti,ab AND after:ti,ab) OR (before:ti,ab AND during:ti,ab) | 1,224,588
#7 | ‘time points’:ti,ab AND (multiple:ti,ab OR one:ti,ab OR two:ti,ab OR three:ti,ab OR four:ti,ab OR five:ti,ab OR six:ti,ab OR seven:ti,ab OR eight:ti,ab OR nine:ti,ab OR ten:ti,ab OR month:ti,ab OR monthly:ti,ab OR day:ti,ab OR days:ti,ab OR daily:ti,ab OR week:ti,ab OR weekly:ti,ab OR hour:ti,ab OR hourly:ti,ab) | 99,174
#8 | #4 OR #5 OR #6 OR #7 | 15,875,500
#9 | #3 AND #8 | 328
#10 | #9 NOT (‘case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR ‘letter’/exp OR ‘note’/exp OR [conference abstract]/lim) | 207
#11 | #10 AND [humans]/lim | 201

### Database: CINAHL (via EBSCO)

#### Search date: 6/28/2019

#1 | (MH “Osteoporosis”) OR (MH “Osteoporotic Fractures”) OR (MH “Bone Diseases, Metabolic”) OR (MH “Bone Density”) OR TI (osteoporosis OR osteoporoses OR osteoporotic OR osteopenia OR osteopenias OR osteopenic OR “bone loss” OR “bone losses” OR “bone mineral density” OR “bone mineral densities” OR BMD OR “bone mineral content” OR “bone mineral contents” OR “bone density” OR “bone densities” OR “bone demineralization” OR “bone dimineralizations” OR “bone decalcification” OR “bone decalcifications” OR “fragility fracture” OR “fragility fractures” OR “bone fragility” OR “bone fragilities”) OR AB (osteoporosis OR osteoporoses OR osteoporotic OR osteopenia OR osteopenias OR osteopenic OR “bone loss” OR “bone losses” OR “bone mineral density” OR “bone mineral densities” OR BMD OR “bone mineral content” OR “bone mineral contents” OR “bone density” OR “bone densities” OR “bone demineralization” OR “bone dimineralizations” OR “bone decalcification” OR “bone decalcifications” OR “fragility fracture” OR “fragility fractures” OR “bone fragility” OR “bone fragilities”) | 41,298
#2 | (MH “Veterans+”) OR (MH “Vietnam Veterans”) OR (MH “United States Department of Veterans Affairs”) OR (MH “Hospitals, Veterans”) OR (MH “War+”) OR (MH “Biological Warfare”) OR (MH “Chemical Warfare”) OR (MH “Military Deployment+”) OR (MH “Overseas Deployment”) OR (MH “Nuclear Warfare”) OR TI (Veteran OR veterans OR “Afghan Campaign” OR “Afghan War” OR “Operation Enduring Freedom” OR “Operation New Dawn” OR “Operation Iraqi Freedom” OR “Gulf War” OR “Iraq War” OR “Operation Desert Shield” OR “Operation Desert Storm” OR “Vietnam War” OR “Viet Nam War” OR “Vietnam Conflict” OR “Viet Nam Conflict” OR “Vietnamese War” OR “Vietnamese Conflict” OR “Indochina War” OR “Korean War” OR “World War I” OR “World War II” OR WWI OR WWII) OR AB (Veteran OR veterans OR “Afghan Campaign” OR “Afghan War” OR “Operation Enduring Freedom” OR “Operation New Dawn” OR “Operation Iraqi Freedom” OR “Gulf War” OR “Iraq War” OR “Operation Desert Shield” OR “Operation Desert Storm” OR “Vietnam War” OR “Viet Nam War” OR “Vietnam Conflict” OR “Viet Nam Conflict” OR “Vietnamese War” OR “Vietnamese Conflict” OR “Indochina War” OR “Korean War” OR “World War I” OR “World War II” OR WWI OR WWII) | 39,683
#3 | #1 AND #2 | 110
#4 | (MH “Randomized Controlled Trials+”) OR TI (“randomized controlled trial” OR “controlled clinical trial” OR “randomized” OR “randomization” OR “randomised” OR “randomisation” OR “randomly” OR “trial” OR “groups” OR “comparative study” OR “nonrandom” OR “non-random” OR “nonrandomized” OR “non-randomized” OR “nonrandomised” OR “non-randomised” OR quasi-experiment* OR quasiexperiment* OR quasirandom* OR quasi-random* OR quasi-control* OR quasicontrol* OR (controlled AND (trial OR study)) OR “pre-post” OR “posttest” OR “post-test” OR “pretest” OR “pre-test” OR “repeated measure” OR “repeated measures” OR (“time series” AND “interrupt”) OR (“time points” AND (multiple OR one OR two OR three OR four OR five OR six OR seven OR eight OR nine OR ten OR month OR monthly OR day OR daily OR week OR weekly OR hour OR hourly)) OR (before AND after) OR (before AND during)) OR AB (“randomized controlled trial” OR “controlled clinical trial” OR “randomized” OR “randomization” OR “randomised” OR “randomisation” OR “randomly” OR “trial” OR “groups” OR “comparative study” OR “nonrandom” OR “non-random” OR “nonrandomized” OR “non-randomized” OR “nonrandomised” OR “non-randomised” OR quasi-experiment* OR quasiexperiment* OR quasirandom* OR quasi-random* OR quasi-control* OR quasicontrol* OR (controlled AND (trial OR study)) OR “pre-post” OR “posttest” OR “post-test” OR “pretest” OR “pre-test” “repeated measure” OR “repeated measures” OR (“time series” AND “interrupt”) OR (“time points” AND (multiple OR one OR two OR three OR four OR five OR six OR seven OR eight OR nine OR ten OR month OR monthly OR day OR daily OR week OR weekly OR hour OR hourly)) OR (before AND after) OR (before AND during)) | 748,301
#5 | #3 AND #4 | 20
#6 | #5 NOT PT ( Abstract OR Book OR Book Chapter OR Book Review OR Case Study OR Commentary OR Doctoral Dissertation OR Editorial OR Letter OR Masters Thesis OR Pamphlet OR Pamphlet Chapter OR Poetry ) NOT TI ( Editorial OR Letter OR “Case Report” OR Comment ) | 19

## KEY QUESTION 3

### Database: MEDLINE (via PubMed)

#### Search date: 7/22/2019

#1 | “Osteoporosis”[Mesh:NoExp] OR “Bone Density”[Mesh] OR “Bone Diseases, Metabolic”[Mesh:NoExp] OR “Osteoporotic Fractures”[Mesh] OR osteoporosis[tiab] OR osteoporoses[tiab] OR osteoporotic[tiab] OR osteopenia[tiab] OR osteopenias[tiab] OR osteopenic[tiab] OR osteopaenia[tiab] OR osteopaenias[tiab] OR osteopaenic[tiab] OR “bone loss”[tiab] OR “bone losses”[tiab] OR “bone mineral density”[tiab] OR “bone mineral densities”[tiab] OR BMD[tiab] OR “bone mineral content”[tiab] OR “bone mineral contents”[tiab] OR “bone density”[tiab] OR “bone densities”[tiab] OR “bone demineralization”[tiab] OR “bone dimineralizations”[tiab] OR “bone decalcification”[tiab] OR “bone decalcifications”[tiab] OR “fragility fracture”[tiab] OR “fragility fractures”[tiab] OR “bone fragility”[tiab] OR “bone fragilities”[tiab] | 144,719
#2 | “Risk assessment”[Mesh] OR “Mass screening”[Mesh] OR “Early Diagnosis”[Mesh:NoExp] OR “Absorptiometry, Photon”[Mesh] OR “Densitometry”[Mesh] OR “Ultrasonography”[Mesh] OR “Tomography, X-Ray Computed”[Mesh] OR risk[tiab] OR risks[tiab] OR screening[tiab] OR screenings[tiab] OR marker[tiab] OR markers[tiab] OR detect[tiab] OR detects[tiab] OR detection[tiab] OR detections[tiab] OR detected[tiab] OR “case finding”[tiab] OR “case findings”[tiab] OR “incidental finding”[tiab] OR “incidental findings”[tiab] OR “incidental detection”[tiab] OR “incidental detections”[tiab] OR DEXA[tiab] OR DXA[tiab] OR “dual-energy x-ray”[tiab] OR absorptiometry[tiab] OR Ultrasonography[tiab] OR ultrasonographies[tiab] OR ultrasound[tiab] OR ultrasounds[tiab] OR “computed tomography”[tiab] OR “CT scan”[tiab] OR “CT scans”[tiab] OR densitometry[tiab] OR densitometries[tiab] OR densitometer[tiab] OR densitometers[tiab] OR photodensitometry[tiab] OR “digital x-ray radiogrammetry”[tiab] OR DXR[tiab] OR “fracture prediction”[tiab] OR “fracture predictions”[tiab] OR “fracture assessment”[tiab] OR “fracture assessments”[tiab] OR “fracture estimation”[tiab] OR “fracture estimations”[tiab] OR FRAX[tiab] OR OST[tiab] OR “Self-Assessment Tool”[tiab] OR ORAI[tiab] OR OSTA[tiab] OR “Osteoporosis Self-assessment Tool for Asians”[tiab] OR OSIRIS[tiab] OR SOFSURF[tiab] OR “Male Osteoporosis Screening Tool”[tiab] OR OPRA[tiab] OR FRISK[tiab] OR FRC[tiab] OR MSCORE[tiab] OR MORES[tiab] OR QFracture[tiab] OR “Q Fracture”[tiab] | 5,552,090
#3 | (“Reminder systems”[Mesh] OR systems[tiab] OR “system-level”[tiab] OR “systems-level”[tiab] OR “health system”[tiab] OR reminder[tiab] OR reminders[tiab] OR alert[tiab] OR alerts[tiab] OR notification[tiab] OR notifications[tiab] OR prompt[tiab] OR prompts[tiab] OR automate[tiab] OR automates[tiab] OR automated[tiab] OR automation[tiab] OR mail[tiab] OR mailing[tiab] OR mailed[tiab] OR email[tiab] OR emails[tiab] OR emailed[tiab] OR “text message”[tiab] OR “text messages”[tiab] OR “electronic communication”[tiab] OR “electronic communications”[tiab] OR phone[tiab] OR phoned[tiab] OR phones[tiab] OR telephone[tiab] OR telephoned[tiab] OR telephones[tiab] OR pamphlet[tiab] OR pamphlets[tiab] OR brochure[tiab] OR brochures[tiab] OR coordinate[tiab] OR coordinates[tiab] OR coordinated[tiab] OR coordination[tiab] OR “models of care”[tiab] OR “model of care”[tiab] OR “care model”[tiab] OR “care models”[tiab] OR “case manage”[tiab] OR “case manager”[tiab] OR “case managers”[tiab] OR “case management”[tiab] OR “fracture liaison”[tiab] OR “fracture liaisons”[tiab] OR “bone health clinic”[tiab] OR “bone health clinics”[tiab] OR “Project ECHO”[tiab] OR “Extension for Community Healthcare Outcomes”[tiab] OR “academic detailing”[tiab] OR “multi-modal care”[tiab] OR “multimodal care”[tiab] OR “remote consultation”[tiab] OR “remote consultations”[tiab] OR “self-referral”[tiab] OR “self referral”[tiab] OR “self-referrals”[tiab] OR “self referrals”[tiab] OR “self schedule”[tiab] OR “self-schedule”[tiab] OR “self scheduled”[tiab] OR “self-scheduled”[tiab] OR “self scheduling”[tiab] OR “self-scheduling”[tiab] OR (self[tiab] AND (schedule[tiab] OR schedules[tiab] OR scheduled[tiab] OR scheduling[tiab])) | 1,399,427
#4 | (“Education, Continuing”[Mesh:NoExp] OR “Education, Medical, Continuing”[Mesh] OR “Education, Nursing, Continuing”[Mesh] OR “Physicians/education”[Mesh] OR “Nurses/education”[Mesh] OR ((education[tiab] OR educate[tiab] OR educates[tiab] OR educated[tiab] OR educating[tiab]) AND (physician[tiab] OR physicians[tiab] OR doctor[tiab] OR doctors[tiab] OR provider[tiab] OR providers[tiab] OR patient[tiab] OR patients[tiab] OR clinician[tiab] OR clinicians[tiab] OR nurse[tiab] OR nurses[tiab] OR pharmacist[tiab] OR pharmacists[tiab] OR “hospital staff”[tiab] OR “health personnel”[tiab] OR “health staff”[tiab] OR “clinic staff”[tiab] OR “clinic personnel”[tiab]))) | 254,571
#5 | (“Reimbursement mechanisms”[Mesh] OR ((financial[tiab] OR economic[tiab] OR physician[tiab] OR physicians[tiab] OR doctor[tiab] OR doctors[tiab] OR clinician[tiab] OR clinicians[tiab] OR reimbursement[tiab]) AND (incentive[tiab] OR incentives[tiab]))) | 45,609
#6 | (“Decision Making, Computer-Assisted”[Mesh] OR ((computer[tiab] OR computers[tiab]) AND (decision[tiab] OR decisions[tiab]) AND (support[tiab] OR aid[tiab] OR assisted[tiab]))) | 139,295
#7 | (“Interdisciplinary Communication”[Mesh] OR ((“provider-to-provider”[tiab] OR “physician-to-physician”[tiab] OR “doctor-to-doctor”[tiab] OR “nurse-to-nurse”[tiab] OR “physician-to-nurse”[tiab] OR “nurse-to-physician”[tiab]) AND (consult[tiab] OR consultation[tiab] OR consultations[tiab] OR communication[tiab] OR communications[tiab]))) | 16,436
#8 | (((“Nurses”[Mesh] OR “Nurse’s Role”[Mesh] OR “Nursing Process”[Mesh] OR “Nursing Staff”[Mesh:NoExp] OR “Pharmacists”[Mesh] OR nurse[tiab] OR nursing[tiab] OR nurses[tiab] OR pharmacist[tiab] OR pharmacists[tiab]))) AND (((((“Diagnostic Tests, Routine”[Mesh] OR “Medication Therapy Management”[Mesh] OR “Referral and Consultation”[Mesh] OR driven[tiab] OR intervention[tiab] OR interventions[tiab] OR managed[tiab] OR run[tiab] OR led[tiab] OR implemented[tiab] OR clinic[tiab] OR clinics[tiab]))) OR (((medication[tiab] OR drug[tiab] OR drugs[tiab]) AND (adjust[tiab] OR adjustment[tiab] OR manage[tiab] OR management[tiab] OR initiate[tiab] OR initiated[tiab])) AND (adjust[tiab] OR adjustment[tiab] OR manage[tiab] OR management[tiab] OR initiate[tiab] OR initiated[tiab]))) OR (((order[tiab] OR ordered[tiab] OR ordering[tiab])) AND (diagnostic[tiab] OR test[tiab] OR tests[tiab]))) | 98,222
#9 | #3 OR #4 OR #5 OR #6 OR #7 OR #8 | 1,853,457
#10 | #1 AND #2 AND #9 | 4,268
#11 | “randomized controlled trial”[ptyp] OR “controlled clinical trial”[ptyp] OR randomized[tiab] OR randomised[tiab] OR randomization[tiab] OR randomisation[tiab] OR placebo[tiab] OR randomly[tiab] OR trial[tiab] OR groups[tiab] OR “Comparative Study”[ptyp] OR “clinical trial”[pt] OR “clinical trial”[tiab] OR “clinical trials”[tiab] OR “evaluation studies”[ptyp] OR “evaluation studies as topic”[MeSH] OR “evaluation study”[tiab] OR “evaluation studies”[tiab] OR “intervention study”[tiab] OR “intervention studies”[tiab] OR “cohort studies”[MeSH] OR cohort[tiab] OR “longitudinal studies”[MeSH] OR longitudinal[tiab] OR longitudinally[tiab] OR prospective[tiab] OR prospectively[tiab] OR “follow up”[tiab] OR “comparative study”[pt] OR “comparative studies”[tiab] OR nonrandom[tiab] OR “non-random”[tiab] OR nonrandomized[tiab] OR “non-randomized”[tiab] OR nonrandomised[tiab] OR “non-randomised”[tiab] OR quasi-experiment*[tiab] OR quasiexperiment*[tiab] OR quasirandom*[tiab] OR quasi-random*[tiab] OR quasi-control*[tiab] OR quasicontrol*[tiab] OR ((controlled[tiab]) AND (trial[tiab] OR study[tiab])) | 7,198,417
#12 | “pre-post”[tiab] OR “posttest”[tiab] OR “post-test”[tiab] OR pretest[tiab] OR “pre-test”[tiab] OR “repeated measure”[tiab] OR “repeated measures”[tiab] | 67,071
#13 | (before[tiab] AND after[tiab]) OR (before[tiab] AND during[tiab]) | 108
#14 | “time series”[tiab] AND interrupt*[tiab] | 2,707
#15 | (“time points”[tiab]) AND (multiple[tiab] OR one[tiab] OR two[tiab] OR three[tiab] OR four[tiab] OR five[tiab] OR six[tiab] OR seven[tiab] OR eight[tiab] OR nine[tiab] OR ten[tiab] OR month[tiab] OR monthly[tiab] OR day[tiab] OR daily[tiab] OR week[tiab] OR weekly[tiab] OR hour[tiab] OR hourly[tiab]) | 59,441
#16 | #11 OR #12 OR #13 OR #14 OR #15 | 7,237,642
#17 | #10 AND #16 | 2,337

### MEDLINE (via PubMed) Search update

#### Search date: 2/23/2021

#1 | “Osteoporosis”[Mesh:NoExp] OR “Bone Density”[Mesh] OR “Bone Diseases, Metabolic”[Mesh:NoExp] OR “Osteoporotic Fractures”[Mesh] OR osteoporosis[tiab] OR osteoporoses[tiab] OR osteoporotic[tiab] OR osteopenia[tiab] OR osteopenias[tiab] OR osteopenic[tiab] OR osteopaenia[tiab] OR osteopaenias[tiab] OR osteopaenic[tiab] OR “bone loss”[tiab] OR “bone losses”[tiab] OR “bone mineral density”[tiab] OR “bone mineral densities”[tiab] OR BMD[tiab] OR “bone mineral content”[tiab] OR “bone mineral contents”[tiab] OR “bone density”[tiab] OR “bone densities”[tiab] OR “bone demineralization”[tiab] OR “bone dimineralizations”[tiab] OR “bone decalcification”[tiab] OR “bone decalcifications”[tiab] OR “fragility fracture”[tiab] OR “fragility fractures”[tiab] OR “bone fragility”[tiab] OR “bone fragilities”[tiab] | 158,618
#2 | “Risk assessment”[Mesh] OR “Mass screening”[Mesh] OR “Early Diagnosis”[Mesh:NoExp] OR “Absorptiometry, Photon”[Mesh] OR “Densitometry”[Mesh] OR “Ultrasonography”[Mesh] OR “Tomography, X-Ray Computed”[Mesh] OR risk[tiab] OR risks[tiab] OR screening[tiab] OR screenings[tiab] OR marker[tiab] OR markers[tiab] OR detect[tiab] OR detects[tiab] OR detection[tiab] OR detections[tiab] OR detected[tiab] OR “case finding”[tiab] OR “case findings”[tiab] OR “incidental finding”[tiab] OR “incidental findings”[tiab] OR “incidental detection”[tiab] OR “incidental detections”[tiab] OR DEXA[tiab] OR DXA[tiab] OR “dual-energy x-ray”[tiab] OR absorptiometry[tiab] OR Ultrasonography[tiab] OR ultrasonographies[tiab] OR ultrasound[tiab] OR ultrasounds[tiab] OR “computed tomography”[tiab] OR “CT scan”[tiab] OR “CT scans”[tiab] OR densitometry[tiab] OR densitometries[tiab] OR densitometer[tiab] OR densitometers[tiab] OR photodensitometry[tiab] OR “digital x-ray radiogrammetry”[tiab] OR DXR[tiab] OR “fracture prediction”[tiab] OR “fracture predictions”[tiab] OR “fracture assessment”[tiab] OR “fracture assessments”[tiab] OR “fracture estimation”[tiab] OR “fracture estimations”[tiab] OR FRAX[tiab] OR OST[tiab] OR “Self-Assessment Tool”[tiab] OR ORAI[tiab] OR OSTA[tiab] OR “Osteoporosis Self-assessment Tool for Asians”[tiab] OR OSIRIS[tiab] OR SOFSURF[tiab] OR “Male Osteoporosis Screening Tool”[tiab] OR OPRA[tiab] OR FRISK[tiab] OR FRC[tiab] OR MSCORE[tiab] OR MORES[tiab] OR QFracture[tiab] OR “Q Fracture”[tiab] | 6,211,,363
#3 | (“Reminder systems”[Mesh] OR systems[tiab] OR “system-level”[tiab] OR “systems-level”[tiab] OR “health system”[tiab] OR reminder[tiab] OR reminders[tiab] OR alert[tiab] OR alerts[tiab] OR notification[tiab] OR notifications[tiab] OR prompt[tiab] OR prompts[tiab] OR automate[tiab] OR automates[tiab] OR automated[tiab] OR automation[tiab] OR mail[tiab] OR mailing[tiab] OR mailed[tiab] OR email[tiab] OR emails[tiab] OR emailed[tiab] OR “text message”[tiab] OR “text messages”[tiab] OR “electronic communication”[tiab] OR “electronic communications”[tiab] OR phone[tiab] OR phoned[tiab] OR phones[tiab] OR telephone[tiab] OR telephoned[tiab] OR telephones[tiab] OR pamphlet[tiab] OR pamphlets[tiab] OR brochure[tiab] OR brochures[tiab] OR coordinate[tiab] OR coordinates[tiab] OR coordinated[tiab] OR coordination[tiab] OR “models of care”[tiab] OR “model of care”[tiab] OR “care model”[tiab] OR “care models”[tiab] OR “case manage”[tiab] OR “case manager”[tiab] OR “case managers”[tiab] OR “case management”[tiab] OR “fracture liaison”[tiab] OR “fracture liaisons”[tiab] OR “bone health clinic”[tiab] OR “bone health clinics”[tiab] OR “Project ECHO”[tiab] OR “Extension for Community Healthcare Outcomes”[tiab] OR “academic detailing”[tiab] OR “multi-modal care”[tiab] OR “multimodal care”[tiab] OR “remote consultation”[tiab] OR “remote consultations”[tiab] OR “self-referral”[tiab] OR “self referral”[tiab] OR “self-referrals”[tiab] OR “self referrals”[tiab] OR “self schedule”[tiab] OR “self-schedule”[tiab] OR “self scheduled”[tiab] OR “self-scheduled”[tiab] OR “self scheduling”[tiab] OR “self-scheduling”[tiab] OR (self[tiab] AND (schedule[tiab] OR schedules[tiab] OR scheduled[tiab] OR scheduling[tiab]))) | 1,590,094
#4 | (“Education, Continuing”[Mesh:NoExp] OR “Education, Medical, Continuing”[Mesh] OR “Education, Nursing, Continuing”[Mesh] OR “Physicians/education”[Mesh] OR “Nurses/education”[Mesh] OR ((education[tiab] OR educate[tiab] OR educates[tiab] OR educated[tiab] OR educating[tiab]) AND (physician[tiab] OR physicians[tiab] OR doctor[tiab] OR doctors[tiab] OR provider[tiab] OR providers[tiab] OR patient[tiab] OR patients[tiab] OR clinician[tiab] OR clinicians[tiab] OR nurse[tiab] OR nurses[tiab] OR pharmacist[tiab] OR pharmacists[tiab] OR “hospital staff”[tiab] OR “health personnel”[tiab] OR “health staff”[tiab] OR “clinic staff”[tiab] OR “clinic personnel”[tiab]))) | 286,583
#5 | (“Reimbursement mechanisms”[Mesh] OR ((financial[tiab] OR economic[tiab] OR physician[tiab] OR physicians[tiab] OR doctor[tiab] OR doctors[tiab] OR clinician[tiab] OR clinicians[tiab] OR reimbursement[tiab]) AND (incentive[tiab] OR incentives[tiab]))) | 48,129
#6 | (“Decision Making, Computer-Assisted”[Mesh] OR ((computer[tiab] OR computers[tiab]) AND (decision[tiab] OR decisions[tiab]) AND (support[tiab] OR aid[tiab] OR assisted[tiab]))) | 127,513
#7 | (“Interdisciplinary Communication”[Mesh] OR ((“provider-to-provider”[tiab] OR “physician-to-physician”[tiab] OR “doctor-to-doctor”[tiab] OR “nurse-to-nurse”[tiab] OR “physician-to-nurse”[tiab] OR “nurse-to-physician”[tiab]) AND (consult[tiab] OR consultation[tiab] OR consultations[tiab] OR communication[tiab] OR communications[tiab]))) | 17,763
#8 | ((“Nurses”[Mesh] OR “Nurse’s Role”[Mesh] OR “Nursing Process”[Mesh] OR “Nursing Staff”[Mesh:NoExp] OR “Pharmacists”[Mesh] OR nurse[tiab] OR nursing[tiab] OR nurses[tiab] OR pharmacist[tiab] OR pharmacists[tiab]) AND ((“Diagnostic Tests, Routine”[Mesh] OR “Medication Therapy Management”[Mesh] OR “Referral and Consultation”[Mesh] OR driven[tiab] OR intervention[tiab] OR interventions[tiab] OR managed[tiab] OR run[tiab] OR led[tiab] OR implemented[tiab] OR clinic[tiab] OR clinics[tiab]) OR ((medication[tiab] OR drug[tiab] OR drugs[tiab]) AND (adjust[tiab] OR adjustment[tiab] OR manage[tiab] OR management[tiab] OR initiate[tiab] OR initiated[tiab])) OR ((order[tiab] OR ordered[tiab] OR ordering[tiab]) AND (diagnostic[tiab] OR test[tiab] OR tests[tiab])))) | 112,316
#9 | #3 OR #4 OR #5 OR #6 OR #7 OR #8 | 2,071,224
#10 | #1 AND #2 AND #9 | 4,699
#11 | “randomized controlled trial”[ptyp] OR “controlled clinical trial”[ptyp] OR randomized[tiab] OR randomised[tiab] OR randomization[tiab] OR randomisation[tiab] OR placebo[tiab] OR randomly[tiab] OR trial[tiab] OR groups[tiab] OR “Comparative Study”[ptyp] OR “clinical trial”[pt] OR “clinical trial”[tiab] OR “clinical trials”[tiab] OR “evaluation studies”[ptyp] OR “evaluation studies as topic”[MeSH] OR “evaluation study”[tiab] OR “evaluation studies”[tiab] OR “intervention study”[tiab] OR “intervention studies”[tiab] OR “cohort studies”[MeSH] OR cohort[tiab] OR “longitudinal studies”[MeSH] OR longitudinal[tiab] OR longitudinally[tiab] OR prospective[tiab] OR prospectively[tiab] OR “follow up”[tiab] OR “comparative study”[pt] OR “comparative studies”[tiab] OR nonrandom[tiab] OR “non-random”[tiab] OR nonrandomized[tiab] OR “non-randomized”[tiab] OR nonrandomised[tiab] OR “non-randomised”[tiab] OR quasi-experiment*[tiab] OR quasiexperiment*[tiab] OR quasirandom*[tiab] OR quasi-random*[tiab] OR quasi-control*[tiab] OR quasicontrol*[tiab] OR ((controlled[tiab]) AND (trial[tiab] OR study[tiab])) | 7,790,112
#12 | “pre-post”[tiab] OR “posttest”[tiab] OR “post-test”[tiab] OR pretest[tiab] OR “pre-test”[tiab] OR “repeated measure”[tiab] OR “repeated measures”[tiab] | 79,063
#13 | (before[tiab] AND after[tiab]) OR (before[tiab] AND during[tiab]) | 68
#14 | “time series”[tiab] AND interrupt*[tiab] | 3,718
#15 | (“time points”[tiab]) AND (multiple[tiab] OR one[tiab] OR two[tiab] OR three[tiab] OR four[tiab] OR five[tiab] OR six[tiab] OR seven[tiab] OR eight[tiab] OR nine[tiab] OR ten[tiab] OR month[tiab] OR monthly[tiab] OR day[tiab] OR daily[tiab] OR week[tiab] OR weekly[tiab] OR hour[tiab] OR hourly[tiab]) | 68,877
#16 | #11 OR #12 OR #13 OR #14 OR #15 | 7,836,590
#17 | #10 AND #16 | 2,531
#18 | #17 AND (“2019/06/01”[mhda] : “3000”[mhda]) | 378

### Database: EMBASE (via Elsevier)

#### Search date: 7/22/2019

#1 | ‘bone demineralization’/de OR ‘osteoporosis’/de OR ‘corticosteroid induced osteoporosis’/de OR ‘idiopathic osteoporosis’/de OR ‘posttraumatic osteoporosis’/de OR ‘primary osteoporosis’/de OR ‘secondary osteoporosis’/de OR ‘senile osteoporosis’/de OR ‘metabolic bone disease’/de OR ‘bone density’/exp OR ‘fragility fracture’/exp OR osteoporosis:ti,ab OR osteoporoses:ti,ab OR osteoporotic:ti,ab OR osteopenia:ti,ab OR osteopenias:ti,ab OR osteopenic:ti,ab OR osteopaenia:ti,ab OR osteopaenias:ti,ab OR osteopaenic:ti,ab OR ‘bone loss’:ti,ab OR ‘bone losses’:ti,ab OR ‘bone mineral density’:ti,ab OR ‘bone mineral densities’:ti,ab OR BMD:ti,ab OR ‘bone mineral content’:ti,ab OR ‘bone mineral contents’:ti,ab OR ‘bone density’:ti,ab OR ‘bone densities’:ti,ab OR ‘bone demineralization’:ti,ab OR ‘bone dimineralizations’:ti,ab OR ‘bone decalcification’:ti,ab OR ‘bone decalcifications’:ti,ab OR ‘fragility fracture’:ti,ab OR ‘fragility fractures’:ti,ab OR ‘bone fragility’:ti,ab OR ‘bone fragilities’:ti,ab | 231,849
#2 | ‘risk assessment’/exp OR ‘mass screening’/exp OR ‘early diagnosis’/exp OR ‘photon absorptiometry’/exp OR ‘densitometry’/exp OR ‘echography’/exp OR ‘computer assisted tomography’/exp OR risk:ti,ab OR risks:ti,ab OR screening:ti,ab OR screenings:ti,ab OR marker:ti,ab OR markers:ti,ab OR detect:ti,ab OR detects:ti,ab OR detection:ti,ab OR detections:ti,ab OR detected:ti,ab OR ‘case finding’:ti,ab OR ‘case findings’:ti,ab OR ‘incidental finding’:ti,ab OR ‘incidental findings’:ti,ab OR ‘incidental detection’:ti,ab OR ‘incidental detections’:ti,ab OR DEXA:ti,ab OR DXA:ti,ab OR ‘dual energy xray’:ti,ab OR absorptiometry:ti,ab OR Ultrasonography:ti,ab OR ultrasonographies:ti,ab OR ultrasound:ti,ab OR ultrasounds:ti,ab OR ‘computed tomography’:ti,ab OR ‘CT scan’:ti,ab OR ‘CT scans’:ti,ab OR densitometry:ti,ab OR densitometries:ti,ab OR densitometer:ti,ab OR densitometers:ti,ab OR photodensitometry:ti,ab OR ‘digital xray radiogrammetry’:ti,ab OR DXR:ti,ab OR ‘fracture prediction’:ti,ab OR ‘fracture predictions’:ti,ab OR ‘fracture assessment’:ti,ab OR ‘fracture assessments’:ti,ab OR ‘fracture estimation’:ti,ab OR ‘fracture estimations’:ti,ab OR FRAX:ti,ab OR OST:ti,ab OR ‘Self Assessment Tool’:ti,ab OR ORAI:ti,ab OR OSTA:ti,ab OR ‘Osteoporosis Self assessment Tool for Asians’:ti,ab OR OSIRIS:ti,ab OR SOFSURF:ti,ab OR ‘Male Osteoporosis Screening Tool’:ti,ab OR OPRA:ti,ab OR FRISK:ti,ab OR FRC:ti,ab OR MSCORE:ti,ab OR MORES:ti,ab OR QFracture:ti,ab OR ‘Q Fracture’:ti,ab | 7,932,430
#3 | (‘reminder system’/exp OR systems:ti,ab OR ‘system level’:ti,ab OR ‘health system’:ti,ab OR reminder:ti,ab OR reminders:ti,ab OR alert:ti,ab OR alerts:ti,ab OR notification:ti,ab OR notifications:ti,ab OR prompt:ti,ab OR prompts:ti,ab OR automate:ti,ab OR automates:ti,ab OR automated:ti,ab OR automation:ti,ab OR mail:ti,ab OR mailing:ti,ab OR mailed:ti,ab OR email:ti,ab OR emails:ti,ab OR emailed:ti,ab OR ‘text message’:ti,ab OR ‘text messages’:ti,ab OR ‘electronic communication’:ti,ab OR ‘electronic communications’:ti,ab OR phone:ti,ab OR phoned:ti,ab OR phones:ti,ab OR telephone:ti,ab OR telephoned:ti,ab OR telephones:ti,ab OR pamphlet:ti,ab OR pamphlets:ti,ab OR brochure:ti,ab OR brochures:ti,ab OR coordinate:ti,ab OR coordinates:ti,ab OR coordinated:ti,ab OR coordination:ti,ab OR ‘models of care’:ti,ab OR ‘model of care’:ti,ab OR ‘care model’:ti,ab OR ‘care models’:ti,ab OR ‘case manage’:ti,ab OR ‘case manager’:ti,ab OR ‘case managers’:ti,ab OR ‘case management’:ti,ab OR ‘fracture liaison’:ti,ab OR ‘fracture liaisons’:ti,ab OR ‘bone health clinic’:ti,ab OR ‘bone health clinics’:ti,ab OR ‘Project ECHO’:ti,ab OR ‘Extension for Community Healthcare Outcomes’:ti,ab OR ‘academic detailing’:ti,ab OR ‘multi modal care’:ti,ab OR ‘multimodal care’:ti,ab OR ‘remote consultation’:ti,ab OR ‘remote consultations’:ti,ab OR ‘self referral’:ti,ab OR ‘self referrals’:ti,ab OR ‘self schedule’:ti,ab OR ‘self scheduled’:ti,ab OR ‘self scheduling’:ti,ab OR (self:ti,ab AND (schedule:ti,ab OR schedules:ti,ab OR scheduled:ti,ab OR scheduling:ti,ab))) | 1,701,895
#4 | (‘continuing education’/exp OR ‘continuing medical education’/exp OR ‘nursing education’/exp OR ((education:ti,ab OR educate:ti,ab OR educates:ti,ab OR educated:ti,ab OR educating:ti,ab) AND (physician:ti,ab OR physicians:ti,ab OR doctor:ti,ab OR doctors:ti,ab OR provider:ti,ab OR providers:ti,ab OR patient:ti,ab OR patients:ti,ab OR clinician:ti,ab OR clinicians:ti,ab OR nurse:ti,ab OR nurses:ti,ab OR pharmacist:ti,ab OR pharmacists:ti,ab OR ‘hospital staff’:ti,ab OR ‘health personnel’:ti,ab OR ‘health staff’:ti,ab OR ‘clinic staff’:ti,ab OR ‘clinic personnel’:ti,ab))) | 396,572
#5 | (‘reimbursement’/exp OR ((financial:ti,ab OR economic:ti,ab OR physician:ti,ab OR physicians:ti,ab OR doctor:ti,ab OR doctors:ti,ab OR clinician:ti,ab OR clinicians:ti,ab OR reimbursement:ti,ab) AND (incentive:ti,ab OR incentives:ti,ab))) | 66,679
#6 | (‘decision support system’/exp OR ((computer:ti,ab OR computers:ti,ab) AND (decision:ti,ab OR decisions:ti,ab) AND (support:ti,ab OR aid:ti,ab OR assisted:ti,ab))) | 25,987
#7 | (‘interdisciplinary communication’/exp OR ((‘provider to provider’:ti,ab OR ‘physician to physician’:ti,ab OR ‘doctor to doctor’:ti,ab OR ‘nurse to nurse’:ti,ab OR ‘physician to nurse’:ti,ab OR ‘nurse to physician’:ti,ab) AND (consult:ti,ab OR consultation:ti,ab OR consultations:ti,ab OR communication:ti,ab OR communications:ti,ab))) | 11,775
#8 | ((‘nurse’/exp OR ‘nurse attitude’/exp OR ‘nursing process’/exp OR ‘nursing staff’/exp OR ‘pharmacist’/exp OR nurse:ti,ab OR nursing:ti,ab OR nurses:ti,ab OR pharmacist:ti,ab OR pharmacists:ti,ab) AND ((‘diagnostic test’/exp OR ‘medication therapy management’/exp OR ‘patient referral’/exp OR driven:ti,ab OR intervention:ti,ab OR interventions:ti,ab OR managed:ti,ab OR run:ti,ab OR led:ti,ab OR implemented:ti,ab OR clinic:ti,ab OR clinics:ti,ab) OR ((medication:ti,ab OR drug:ti,ab OR drugs:ti,ab) AND (adjust:ti,ab OR adjustment:ti,ab OR manage:ti,ab OR management:ti,ab OR initiate:ti,ab OR initiated:ti,ab)) OR ((order:ti,ab OR ordered:ti,ab OR ordering:ti,ab) AND (diagnostic:ti,ab OR test:ti,ab OR tests:ti,ab)))) | 152,884
#9 | #3 OR #4 OR #5 OR #6 OR #7 OR #8 | 2,219,293
#10 | #1 AND #2 AND #9 | 7,592
#11 | ‘randomized controlled trial’/exp OR ‘crossover procedure’/exp OR ‘double blind procedure’/exp OR ‘single blind procedure’/exp OR randomization:ti,ab OR randomisation:ti,ab OR randomized:ti,ab OR randomised:ti,ab OR randomly:ti,ab OR crossover:ti,ab OR ‘cross over’:ti,ab OR placebo:ti,ab OR ‘double blind’:ti,ab OR ‘double blinded’:ti,ab OR ‘single blind’:ti,ab OR ‘single blinded’:ti,ab OR ‘clinical study’/exp OR ‘clinical trial’:ti,ab OR ‘clinical trials’:ti,ab OR ‘controlled study’/exp OR ‘evaluation study’/exp OR ‘evaluation study’:ti,ab OR ‘evaluation studies’:ti,ab OR ‘intervention study’/exp OR ‘intervention study’:ti,ab OR ‘intervention studies’:ti,ab OR ‘case control study’/exp OR ‘case control’:ti,ab OR ‘cohort analysis’/exp OR cohort:ti,ab OR cohorts:ti,ab OR longitudinal:ti,ab OR longitudinally:ti,ab OR prospective:ti,ab OR prospectively:ti,ab OR retrospective:ti,ab OR ‘follow up’/exp OR ‘follow up’:ti,ab OR ‘comparative effectiveness’/exp OR ‘comparative study’/exp OR ‘comparative study’:ti,ab OR ‘comparative studies’:ti,ab OR nonrandom:ti,ab OR ‘non random’:ti,ab OR nonrandomized:ti,ab OR ‘non randomized’:ti,ab OR nonrandomised:ti,ab OR ‘non randomised’:ti,ab OR quasiexperiment*:ti,ab OR quasirandom*:ti,ab OR quasicontrol*:ti,ab OR ((controlled:ti,ab) AND (trial:ti,ab OR study:ti,ab)) | 15,592,201
#12 | ‘pre post’:ti,ab OR ‘posttest’:ti,ab OR ‘post test’:ti,ab OR pretest:ti,ab OR ‘pre test’:ti,ab OR ‘repeated measure’:ti,ab OR ‘repeated measures’:ti,ab | 99,513
#13 | (before:ti,ab AND after:ti,ab) OR (before:ti,ab AND during:ti,ab) | 1,229,709
#14 | ‘time series’:ti,ab AND interrupt*:ti,ab | 3,282
#15 | (‘time points’:ti,ab) AND (multiple:ti,ab OR one:ti,ab OR two:ti,ab OR three:ti,ab OR four:ti,ab OR five:ti,ab OR six:ti,ab OR seven:ti,ab OR eight:ti,ab OR nine:ti,ab OR ten:ti,ab OR month:ti,ab OR monthly:ti,ab OR day:ti,ab OR daily:ti,ab OR week:ti,ab OR weekly:ti,ab OR hour:ti,ab OR hourly:ti,ab) | 95,855
#16 | #11 OR #12 OR #13 OR #14 OR #15 | 16,010,630
#17 | #10 AND #16 | 5,045
#18 | #17 NOT (‘case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR ‘letter’/exp OR ‘note’/exp OR [conference abstract]/lim) | 2,905

### Database: CINAHL Complete (via EBSCO)

#### Search date: 7/22/2019

#1 | (MH “Osteoporosis”) OR (MH “Osteoporotic Fractures”) OR (MH “Bone Diseases, Metabolic”) OR (MH “Bone Density”) OR TI (osteoporosis OR osteoporoses OR osteoporotic OR osteopenia OR osteopenias OR osteopenic OR osteopaenia OR osteopaenias OR osteopaenic OR “bone loss” OR “bone losses” OR “bone mineral density” OR “bone mineral densities” OR BMD OR “bone mineral content” OR “bone mineral contents” OR “bone density” OR “bone densities” OR “bone demineralization” OR “bone dimineralizations” OR “bone decalcification” OR “bone decalcifications” OR “fragility fracture” OR “fragility fractures” OR “bone fragility” OR “bone fragilities”) OR AB (osteoporosis OR osteoporoses OR osteoporotic OR osteopenia OR osteopenias OR osteopenic OR osteopaenia OR osteopaenias OR osteopaenic OR “bone loss” OR “bone losses” OR “bone mineral density” OR “bone mineral densities” OR BMD OR “bone mineral content” OR “bone mineral contents” OR “bone density” OR “bone densities” OR “bone demineralization” OR “bone dimineralizations” OR “bone decalcification” OR “bone decalcifications” OR “fragility fracture” OR “fragility fractures” OR “bone fragility” OR “bone fragilities”) | 41,428
#2 | (MH “Risk Assessment”) OR (MH “Health Screening+”) OR (MH “Early Diagnosis”) OR (MH “Absorptiometry, Photon”) OR (MH “Densitometry+”) OR (MH “Ultrasonography+”) OR (MH “Tomography, X-Ray Computed+”) OR TI (risk OR risks OR screening OR screenings OR marker OR markers OR detect OR detects OR detection OR detections OR detected OR “case finding” OR “case findings” OR “incidental finding” OR “incidental findings” OR “incidental detection” OR “incidental detections” OR DEXA OR DXA OR “dual-energy x-ray” OR absorptiometry OR ultrasonography OR ultrasonographies OR ultrasound OR ultrasounds OR “computed tomography” OR “CT scan” OR “CT scans” OR densitometry OR densitometries OR densitometer OR densitometers OR photodensitometry OR “digital x-ray radiogrammetry” OR DXR OR “fracture prediction” OR “fracture predictions” OR “fracture assessment” OR “fracture assessments” OR “fracture estimation” OR “fracture estimations” OR FRAX OR OST OR “Self-Assessment Tool” OR ORAI OR OSTA OR “Osteoporosis Self-assessment Tool for Asians” OR OSIRIS OR SOFSURF OR “Male Osteoporosis Screening Tool” OR OPRA OR FRISK OR FRC OR MSCORE OR MORES OR QFracture OR “Q Fracture”) OR AB (risk OR risks OR screening OR screenings OR marker OR markers OR detect OR detects OR detection OR detections OR detected OR “case finding” OR “case findings” OR “incidental finding” OR “incidental findings” OR “incidental detection” OR “incidental detections” OR DEXA OR DXA OR “dual-energy x-ray” OR absorptiometry OR ultrasonography OR ultrasonographies OR ultrasound OR ultrasounds OR “computed tomography” OR “CT scan” OR “CT scans” OR densitometry OR densitometries OR densitometer OR densitometers OR photodensitometry OR “digital x-ray radiogrammetry” OR DXR OR “fracture prediction” OR “fracture predictions” OR “fracture assessment” OR “fracture assessments” OR “fracture estimation” OR “fracture estimations” OR FRAX OR OST OR “Self-Assessment Tool” OR ORAI OR OSTA OR “Osteoporosis Self-assessment Tool for Asians” OR OSIRIS OR SOFSURF OR “Male Osteoporosis Screening Tool” OR OPRA OR FRISK OR FRC OR MSCORE OR MORES OR QFracture OR “Q Fracture”) | 1,509,704
#3 | (MH “Reminder Systems”) OR TI (systems OR “system-level” OR “systems-level” OR “health system” OR reminder OR reminders OR alert OR alerts OR notification OR notifications OR prompt OR prompts OR automate OR automates OR automated OR automation OR mail OR mailing OR mailed OR email OR emails OR emailed OR “text message” OR “text messages” OR “electronic communication” OR “electronic communications” OR phone OR phoned OR phones OR telephone OR telephoned OR telephones OR pamphlet OR pamphlets OR brochure OR brochures OR coordinate OR coordinates OR coordinated OR coordination OR “models of care” OR “model of care” OR “care model” OR “care models” OR “case manage” OR “case manager” OR “case managers” OR “case management” OR “fracture liaison” OR “fracture liaisons” OR “bone health clinic” OR “bone health clinics” OR “Project ECHO” OR “Extension for Community Healthcare Outcomes” OR “academic detailing” OR “multi-modal care” OR “multimodal care” OR “remote consultation” OR “remote consultations” OR “self-referral” OR “self referral” OR “self-referrals” OR “self referrals” OR “self schedule” OR “self-schedule” OR “self scheduled” OR “self-scheduled” OR “self scheduling” OR “self-scheduling” OR (self AND (schedule OR schedules OR scheduled OR scheduling)) OR AB (systems OR “system-level” OR “systems-level” OR “health system” OR reminder OR reminders OR alert OR alerts OR notification OR notifications OR prompt OR prompts OR automate OR automates OR automated OR automation OR mail OR mailing OR mailed OR email OR emails OR emailed OR “text message” OR “text messages” OR “electronic communication” OR “electronic communications” OR phone OR phoned OR phones OR telephone OR telephoned OR telephones OR pamphlet OR pamphlets OR brochure OR brochures OR coordinate OR coordinates OR coordinated OR coordination OR “models of care” OR “model of care” OR “care model” OR “care models” OR “case manage” OR “case manager” OR “case managers” OR “case management” OR “fracture liaison” OR “fracture liaisons” OR “bone health clinic” OR “bone health clinics” OR “Project ECHO” OR “Extension for Community Healthcare Outcomes” OR “academic detailing” OR “multi-modal care” OR “multimodal care” OR “remote consultation” OR “remote consultations” OR “self-referral” OR “self referral” OR “self-referrals” OR “self referrals” OR “self schedule” OR “self-schedule” OR “self scheduled” OR “self-scheduled” OR “self scheduling” OR “self-scheduling” OR (self AND (schedule OR schedules OR scheduled OR scheduling)) | 458,949
#4 | (MH “Education, Continuing+”) OR (MH “Physicians+/ED”) OR (MH “Nurses+/ED”) OR TI (((education OR educate OR educates OR educated OR educating) AND (physician OR physicians OR doctor OR doctors OR provider OR providers OR patient OR patients OR clinician OR clinicians OR nurse OR nurses OR pharmacist OR pharmacists OR “hospital staff” OR “health personnel” OR “health staff” OR “clinic staff” OR “clinic personnel”))) OR AB (((education OR educate OR educates OR educated OR educating) AND (physician OR physicians OR doctor OR doctors OR provider OR providers OR patient OR patients OR clinician OR clinicians OR nurse OR nurses OR pharmacist OR pharmacists OR “hospital staff” OR “health personnel” OR “health staff” OR “clinic staff” OR “clinic personnel”))) | 142,630
#5 | (MH “Reimbursement, Incentive”) OR (MH “Reimbursement Mechanisms+”) OR TI (((financial OR economic OR physician OR physicians OR doctor OR doctors OR clinician OR clinicians OR reimbursement) AND (incentive OR incentives))) OR AB (((financial OR economic OR physician OR physicians OR doctor OR doctors OR clinician OR clinicians OR reimbursement) AND (incentive OR incentives))) | 22,473
#6 | (MH “Decision Making, Computer Assisted+”) OR TI ((computer OR computers) AND (decision OR decisions) AND (support OR aid OR assisted)) OR AB ((computer OR computers) AND (decision OR decisions) AND (support OR aid OR assisted)) | 39,456
#7 | (MH “Interprofessional Relations+”) OR (MH “Nurse-Physician Relations”) OR TI ((“provider-to-provider” OR “physician-to-physician” OR “doctor-to-doctor” OR “nurse-to-nurse” OR “physician-to-nurse” OR “nurse-to-physician”) AND (consult OR consultation OR consultations OR communication OR communications)) OR AB ((“provider-to-provider” OR “physician-to-physician” OR “doctor-to-doctor” OR “nurse-to-nurse” OR “physician-to-nurse” OR “nurse-to-physician”) AND (consult OR consultation OR consultations OR communication OR communications)) | 28,405
#8 | (((MH “Nurses+”) OR (MH “Nursing Role”) OR (MH “Nursing Process+”) OR (MH “Nursing Staff, Hospital”) OR (MH “Staff Nurses”) OR (MH “Nurse Liaison”) OR (MH “Nursing Leaders”) OR (MH “Nurse Consultants+”) OR (MH “Nurse Administrators+”) OR (MH “Case Managers”) OR (MH “Advanced Practice Nurses+”) OR (MH “Pharmacists”) OR TI (nurse OR nursing OR nurses OR pharmacist OR pharmacists) OR AB (nurse OR nursing OR nurses OR pharmacist OR pharmacists)) AND ((MH “Diagnostic Tests, Routine”) OR (MH “Medication Management”) OR (MH “Referral and Consultation+”) OR TI (driven OR intervention OR interventions OR managed OR run OR led OR implemented OR clinic OR clinics) OR AB (driven OR intervention OR interventions OR managed OR run OR led OR implemented OR clinic OR clinics))) | 75,332
#9 | #3 OR #4 OR #5 OR #6 OR #7 OR #8 | 694,705
#10 | #1 AND #2 AND #9 | 2,245
#11 | (MH “Randomized Controlled Trials+”) OR TI (“randomized controlled trial” OR “controlled clinical trial” OR “randomized” OR “randomization” OR “randomised” OR “randomisation” OR “randomly” OR “trial” OR “groups” OR “comparative study” OR “nonrandom” OR “non-random” OR “nonrandomized” OR “non-randomized” OR “nonrandomised” OR “non-randomised” OR quasi-experiment* OR quasiexperiment* OR quasirandom* OR quasi-random* OR quasi-control* OR quasicontrol* OR (controlled AND (trial OR study)) OR “pre-post” OR “posttest” OR “post-test” OR “pretest” OR “pre-test” OR “repeated measure” OR “repeated measures” OR (“time series” AND “interrupt”) OR (“time points” AND (multiple OR one OR two OR three OR four OR five OR six OR seven OR eight OR nine OR ten OR month OR monthly OR day OR daily OR week OR weekly OR hour OR hourly)) OR (before AND after) OR (before AND during)) OR AB (“randomized controlled trial” OR “controlled clinical trial” OR “randomized” OR “randomization” OR “randomised” OR “randomisation” OR “randomly” OR “trial” OR “groups” OR “comparative study” OR “nonrandom” OR “non-random” OR “nonrandomized” OR “non-randomized” OR “nonrandomised” OR “non-randomised” OR quasi-experiment* OR quasiexperiment* OR quasirandom* OR quasi-random* OR quasi-control* OR quasicontrol* OR (controlled AND (trial OR study)) OR “pre-post” OR “posttest” OR “post-test” OR “pretest” OR “pre-test” “repeated measure” OR “repeated measures” OR (“time series” AND “interrupt”) OR (“time points” AND (multiple OR one OR two OR three OR four OR five OR six OR seven OR eight OR nine OR ten OR month OR monthly OR day OR daily OR week OR weekly OR hour OR hourly)) OR (before AND after) OR (before AND during)) | 751,483
#12 | #10 AND #11 | 643
#13 | #12 NOT PT ( Abstract OR Book OR Book Chapter OR Book Review OR Case Study OR Commentary OR Doctoral Dissertation OR Editorial OR Letter OR Masters Thesis OR Pamphlet OR Pamphlet Chapter OR Poetry ) NOT TI ( Editorial OR Letter OR “Case Report” OR Comment ) | 612