# References

1 Shishehbor MH, White CJ, Gray BH, . Critical Limb Ischemia: An Expert Statement. Journal of the American College of Cardiology. 2016;68(18):2002–2015.27692726
2 Adam DJ, Beard JD, Cleveland T, . Bypass versus angioplasty in severe ischaemia of the leg (BASIL): multicentre, randomised controlled trial. Lancet. 2005;366(9501):1925–1934.16325694
3 Aigner R, Lechler P, Boese CK, Bockmann B, Ruchholtz S, Frink M. Standardised pre-operative diagnostics and treatment of peripheral arterial disease reduce wound complications in geriatric ankle fractures. International orthopaedics. 2018;42(2):395–400.29243059
4 Moriarty JP, Murad MH, Shah ND, . A systematic review of lower extremity arterial revascularization economic analyses. Journal of vascular surgery. 2011;54(4):1131–1144.e1131.21971093
5 Hynes NMBMBAECDSS. The influence of subintimal angioplasty on level of amputation and limb salvage rates in lower limb critical ischaemia: A 15-year experience. European Journal of Vascular and Endovascular Surgery. 2005;30(3):291–299.15939635
6 Sultan S, Hynes N. Five-year Irish trial of CLI patients with TASC II type C/D lesions undergoing subintimal angioplasty or bypass surgery based on plaque echolucency. Journal of endovascular therapy : an official journal of the International Society of Endovascular Specialists. 2009;16(3):270–283.19642779
7 Korhonen M, Biancari F, Soderstrom M, . Femoropopliteal balloon angioplasty vs. bypass surgery for CLI: a propensity score analysis. European journal of vascular and endovascular surgery : the official journal of the European Society for Vascular Surgery. 2011;41(3):378–384.
8 Katib N, Thomas SD, Lennox AF, Yang JL, Varcoe RL. An Endovascular-First Approach to the Treatment of Critical Limb Ischemia Results in Superior Limb Salvage Rates. Journal of endovascular therapy : an official journal of the International Society of Endovascular Specialists. 2015;22(4):473–481.26012571
9 Higgins JP, Altman DG, Gøtzsche PC, . The Cochrane Collaboration’s tool for assessing risk of bias in randomised trials. Bmj. 2011;343:d5928.22008217
10 Sterne JA, Hernan MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. 2016;355:i4919.27733354
11 GRADE working group. 2014; http://www.gradeworkinggroup.org/. Accessed 09/25/15.
12 Bradbury AW, Adam DJ, Bell J, . Multicentre randomised controlled trial of the clinical and cost-effectiveness of a bypass-surgery-first versus a balloon-angioplasty-first revascularisation strategy for severe limb ischaemia due to infrainguinal disease. The Bypass versus Angioplasty in Severe Ischaemia of the Leg (BASIL) trial. Health technology assessment (Winchester, England). 2010;14(14):1–210, iii–iv.
13 Bradbury AW, Adam DJ, Bell J, . Bypass versus Angioplasty in Severe Ischaemia of the Leg (BASIL) trial: Analysis of amputation free and overall survival by treatment received. Journal of vascular surgery. 2010;51:(5 Suppl):18s–31s.20435259
14 Feinglass J, Rucker-Whitaker C, Lindquist L, McCarthy WJ, Pearce WH. Racial differences in primary and repeat lower extremity amputation: results from a multihospital study. Journal of vascular surgery. 2005;41(5):823–829.15886667
15 Popplewell MA, Davies HOB, Narayanswami J, . A Comparison of Outcomes in Patients with Infrapopliteal Disease Randomised to Vein Bypass or Plain Balloon Angioplasty in the Bypass vs. Angioplasty in Severe Ischaemia of the Leg (BASIL) Trial. European journal of vascular and endovascular surgery : the official journal of the European Society for Vascular Surgery. 2017;54(2):195–201.
16 Barshes NR, Chambers JD, Cohen J, Belkin M. Cost-effectiveness in the contemporary management of critical limb ischemia with tissue loss. Journal of vascular surgery. 2012;56(4):1015–1024.e1011.22854267
17 De Man FHSPRDPA. Drug-eluting stents not for all patients. Netherlands Heart Journal. 2006;14(5):174–176.25696622
18 Barshes NR, Kougias P, Ozaki CK, . Cost-effectiveness of revascularization for limb preservation in patients with marginal functional status. Annals of vascular surgery. 2014;28(1):10–17.24332257
19 Holler DCCVDSJMG. Cost-utility analysis of treating severe peripheral arterial occlusive disease. International Journal of Angiology. 2006;15(1):25–33.
20 Forbes JF, Adam DJ, Bell J, . Bypass versus Angioplasty in Severe Ischaemia of the Leg (BASIL) trial: Health-related quality of life outcomes, resource utilization, and cost-effectiveness analysis. Journal of vascular surgery. 2010;51:(5 Suppl):43s–51s.20435261
21 Stoner MC, Defreitas DJ, Manwaring MM, Carter JJ, Parker FM, Powell CS. Cost per day of patency: understanding the impact of patency and reintervention in a sustainable model of healthcare. Journal of vascular surgery. 2008;48(6):1489–1496.18829227
22 Barshes NR, Belkin M. A framework for the evaluation of “value” and cost-effectiveness in the management of critical limb ischemia. Journal of the American College of Surgeons. 2011;213(4):552–566.e555.21943802
23 Bisdas T, Borowski M, Torsello G. Current practice of first-line treatment strategies in patients with critical limb ischemia. Journal of vascular surgery. 2015;62(4):965–973.e963.26187290
24 Bisdas TBMSKTGAFBKBABDBDDSEFHJG. Endovascular Therapy Versus Bypass Surgery as First-Line Treatment Strategies for Critical Limb Ischemia: Results of the Interim Analysis of the CRITISCH Registry. JACC: Cardiovascular Interventions. 2016;9(24):2557–2565.28007205
25 Bodewes TCF, Darling JD, Deery SE, . Patient selection and perioperative outcomes of bypass and endovascular intervention as first revascularization strategy for infrainguinal arterial disease. Journal of vascular surgery. 2018;67(1):206–216.e202.28844467
26 Darling JD, McCallum JC, Soden PA, . Results for primary bypass versus primary angioplasty/stent for lower extremity chronic limb-threatening ischemia. Journal of vascular surgery. 2017;66(2):466–475.28274753
27 Dosluoglu HH, O’Brien-Irr MS, Lukan J, Harris LM, Dryjski ML, Cherr GS. Does preferential use of endovascular interventions by vascular surgeons improve limb salvage, control of symptoms, and survival of patients with critical limb ischemia? American journal of surgery. 2006;192(5):572–576.17071186
28 Dosluoglu HH, Lall P, Harris LM, Dryjski ML. Long-term limb salvage and survival after endovascular and open revascularization for critical limb ischemia after adoption of endovascular-first approach by vascular surgeons. Journal of vascular surgery. 2012;56(2):361–371.22560307
29 Taylor SM, York JW, Cull DL, Kalbaugh CA, Cass AL, Langan EM, 3rd. Clinical success using patient-oriented outcome measures after lower extremity bypass and endovascular intervention for ischemic tissue loss. Journal of vascular surgery. 2009;50(3):534–541; discussion 541.19592193
30 Tsai TT, Rehring TF, Rogers RK, . The Contemporary Safety and Effectiveness of Lower Extremity Bypass Surgery and Peripheral Endovascular Interventions in the Treatment of Symptomatic Peripheral Arterial Disease. Circulation. 2015;132(21):1999–2011.26362632
31 Cejna MDNMRHW. Long-term follow-up and total cost analysis of in-hospital invasive interdisciplinary treatment of critical limb ischemia: Comparison of surgical and endovascular therapy. CardioVascular and Interventional Radiology. 2011;34 SUPPL. 3:528.
32 Gargiulo NJOCDJ. Analysis of length of stay, cost, and hospital disposition in patients with critical limb ischemia treated with open vs endovascular procedures. Journal of Vascular Surgery. 2011;53(2):556.
33 Kim HJBJTJ. Efficacy and cost-effectiveness of endovascular vs conventional bypass revascularization for critical limb ischemia. Journal of Vascular Surgery. 2012;56(3):880.
34 Darling JD, Bodewes TCF, Deery SE, . Outcomes after first-time lower extremity revascularization for chronic limb-threatening ischemia between patients with and without diabetes. Journal of vascular surgery. 2018;67(4):1159–1169.28947228
35 Dayama A, Tsilimparis N, Kolakowski S, Matolo NM, Humphries MD. Clinical outcomes of bypass-first versus endovascular-first strategy in patients with chronic limb-threatening ischemia due to infrageniculate arterial disease. Journal of vascular surgery. 2019;69(1):156–163.e151.30579443
36 Siracuse JJ, Menard MT, Eslami MH, . Comparison of open and endovascular treatment of patients with critical limb ischemia in the Vascular Quality Initiative. Journal of vascular surgery. 2016;63(4):958–965.e951.26830690
37 Barshes NR, Kougias P, Ozaki CK, Goodney PP, Belkin M. Cost-effectiveness of revascularization for limb preservation in patients with end-stage renal disease. Journal of vascular surgery. 2014;60(2):369–374.e361.24657067
38 Werneck CC, Lindsay TF. Tibial angioplasty for limb salvage in high-risk patients and cost analysis. Annals of vascular surgery. 2009;23(5):554–559.19632085
39 Meyer A, Lang W, Borowski M, Torsello G, Bisdas T. In-hospital outcomes in patients with critical limb ischemia and end-stage renal disease after revascularization. Journal of vascular surgery. 2016;63(4):966–973.26843355
40 Darling JD, O’Donnell TFX, Deery SE, . Outcomes after first-time lower extremity revascularization for chronic limb-threatening ischemia in insulin-dependent diabetic patients. Journal of vascular surgery. 2018;68(5):1455–1464.e1451.30360841