# APPENDIX H Citations for Excluded Publications

## Did not present CLI data separately (n=43)

1 Cambou JP, Aboyans V, Constans J, Lacroix P, Dentans C, Bura A. Characteristics and outcome of patients hospitalised for lower extremity peripheral artery disease in France: the COPART Registry. European journal of vascular and endovascular surgery : the official journal of the European Society for Vascular Surgery. 2010;39(5):577–585.
2 Chang CH, Lin JW, Hsu J, Wu LC, Lai MS. Stent revascularization versus bypass surgery for peripheral artery disease in type 2 diabetic patients - an instrumental variable analysis. Scientific reports. 2016;6:37177.27857178
3 Chase MR, Friedman HS, Navaratnam P, Heithoff K, Simpson RJ, Jr. Comparative Assessment of Medical Resource Use and Costs Associated with Patients with Symptomatic Peripheral Artery Disease in the United States. Journal of managed care & specialty pharmacy. 2016;22(6):667–675.27231794
4 Dosluoglu HH, Cherr GS, Lall P, Harris LM, Dryjski ML. Stenting vs above knee polytetrafluoroethylene bypass for TransAtlantic Inter-Society Consensus-II C and D superficial femoral artery disease. Journal of vascular surgery. 2008;48(5):1166–1174.18692357
5 Dosluoglu HH, Lall P, Cherr GS, Harris LM, Dryjski ML. Role of simple and complex hybrid revascularization procedures for symptomatic lower extremity occlusive disease. Journal of vascular surgery. 2010;51(6):1425–1435.e1421.20488323
6 Egorova NN, Guillerme S, Gelijns A, . An analysis of the outcomes of a decade of experience with lower extremity revascularization including limb salvage, lengths of stay, and safety. Journal of vascular surgery. 2010;51(4):878–885, 885.e871.20045618
7 Feldman ZM, Korayem AH, Png CYM, Lurie JM, Marin ML, Faries PL. Economic evaluation of open bypass and novel endovascular therapies for peripheral arterial disease. Journal of Vascular Surgery. 2017;66(2):e15–e16.
8 Goodney PP, Beck AW, Nagle J, Welch HG, Zwolak RM. National trends in lower extremity bypass surgery, endovascular interventions, and major amputations. Journal of vascular surgery. 2009;50(1):54–60.19481407
9 Goodney PP, Tarulli M, Faerber AE, Schanzer A, Zwolak RM. Fifteen-year trends in lower limb amputation, revascularization, and preventive measures among medicare patients. JAMA surgery. 2015;150(1):84–86.25409197
10 Goueffic Y, Della Schiava N, Thaveau F, . Stenting or Surgery for De Novo Common Femoral Artery Stenosis. JACC Cardiovascular interventions. 2017;10(13):1344–1354.28683941
11 Han SM, Wu B, Eichler CM, . Risk Factors for 30-Day Hospital Readmission in Patients Undergoing Treatment for Peripheral Artery Disease. Vascular and endovascular surgery. 2015;49(3–4):69–74.26145753
12 Hardy N, Boyle E, Madhavan P, O’Neill S, Colgan MP, Martin Z, O’Callaghan A. A comparison of endovascular stenting with open bypass for iliac occlusive disease. Irish Journal of Medical Science. 2017;186(2 Supplement 1):S82.
13 Hedayati N, Brunson A, Li CS, Loja MN, Carson JG, White RH, Romano PS. Higher reintervention rate but similar amputation-free survival with endovascular procedures for peripheral arterial disease compared to bypass surgery. Circulation: Cardiovascular Quality and Outcomes. 2012;5(3):2012–2005.
14 Hong JB, Jeon YS, Cho SG, Kim, JY, Hong KC. Endovascular treatment as a reasonable option for extensive total occlusion of iliac artery. American Journal of Cardiology. 2012;109(7 SUPPL. 1):138S–139S.
15 Hong MS, Beck AW, Nelson PR. Emerging national trends in the management and outcomes of lower extremity peripheral arterial disease. Annals of vascular surgery. 2011;25(1):44–54.21172580
16 Hunt NA, Liu GT, Lavery LA. The economics of limb salvage in diabetes. Plastic and reconstructive surgery. 2011;127: Suppl 1:289s–295s.21200304
17 Indes JE, Mandawat A, Tuggle CT, Muhs B, Sosa JA. Endovascular procedures for aorto-iliac occlusive disease are associated with superior short-term clinical and economic outcomes compared with open surgery in the inpatient population. Journal of vascular surgery. 2010;52(5):1173–1179, 1179.e1171.20691560
18 Indes JE, Tuggle CT, Mandawat A, Sosa JA. Age-stratified outcomes in elderly patients undergoing open and endovascular procedures for aortoiliac occlusive disease. Surgery. 2010;148(2):420–428.20580044
19 Islam J, Robbs JV. Comparison between superficial femoral artery stenting and bypass surgery in severe lower-limb ischaemia: a retrospective study. Cardiovascular journal of Africa. 2015;26(1):34–37.25784315
20 Jaff MR, Cahill KE, Yu AP, Birnbaum HG, Engelhart LM. Clinical outcomes and medical care costs among medicare beneficiaries receiving therapy for peripheral arterial disease. Annals of vascular surgery. 2010;24(5):577–587.20579582
21 Janczak D, Malinowski M, Bakowski W, . Comparison of the Incidence of Complications and Secondary Surgical Interventions Necessary in Patients with Chronic Lower Limb Ischemia Treated by Both Open and Endovascular Surgeries. Annals of thoracic and cardiovascular surgery : official journal of the Association of Thoracic and Cardiovascular Surgeons of Asia. 2017;23(3):135–140.
22 Jones WS, Mi X, Qualls LG, . Trends in settings for peripheral vascular intervention and the effect of changes in the outpatient prospective payment system. Journal of the American College of Cardiology. 2015;65(9):920–927.25744009
23 Lepantalo M, Laurila K, Roth WD, . PTFE bypass or thrupass for superficial femoral artery occlusion? A randomised controlled trial. European journal of vascular and endovascular surgery : the official journal of the European Society for Vascular Surgery. 2009;37(5):578–584.
24 Linni K, Ugurluoglu A, Hitzi W, Aspalter M, Holzenbein T. Bioabsorbable stent implantation vs common femoral artery endarterectomy: Early results of a randomized trial. Journal of Endovascular Therapy. 2014;21(4):493–502.25101576
25 Mahoney EM, Wang K, Keo HH, Duval S, Smolderen KG, Cohen DJ, Steg G, Bhatt DL, Hirsch AT. Vascular hospitalization rates and costs in patients with peripheral artery disease in the United States. Circulation: Cardiovascular Quality and Outcomes. 2010;3(6):642–651.20940249
26 McQuade K, Gable D, Pearl G, Theune B, Black S. Four-year randomized prospective comparison of percutaneous ePTFE/nitinol self-expanding stent graft versus prosthetic femoral-popliteal bypass in the treatment of superficial femoral artery occlusive disease. Journal of vascular surgery. 2010;52(3):584–590; discussion 590-581, 591.e581-591.e587.20598480
27 Mehta M, Ramay F, Roddy SP, Kreienberg PB, Sternbach Y, Paty PSK, Taggert JB, Ozsvath KJ, Change BB, Shah DM, Darling RC. Cost per day of patency: Long-term implications of patency and reinterventions after endovascular vs surgical lower extremity revascularizations. Journal of Vascular Surgery. 2011;54(4):1227–1228.
28 Nascimento BR, Brant LC, Lana MLL, Lopes EL, Ribeiro ALP. Recent trends in procedure type, morbidity and in-hospital outcomes of patients with peripheral artery disease: Data from the Brazilian public health system. Circulation. 2014;130(25):2014–2011.
29 Ngu N, Lisik J, Varma D, Goh G.. A retrospective cost analysis of angioplasty compared to bypass surgery for lower limb arterial disease in an Australian tertiary health service. Journal of Medical Imaging and Radiation Oncology. 2017;61 Supplement 1:37.
30 Niazi K, Wallace KL, Grabner M. Long-term costs of directional atherectomy vs Other treatment choices for diabetes patients with peripheral artery disease: A 24-month analysis of administrative claims data. Journal of the American College of Cardiology. 2014;64(11 SUPPL. 1):B40.
31 Ochoa Chaar CIN, Leers S, Marone L, Cho J, Baril DT, Fernandez N, Jeyabalan G, Rhee RY, Makaroun MS, Chaer RA. Lower extremity revascularization (LER) in young patients: Have endovascular options impacted practice and outcomes? Journal of Vascular Surgery. 2010;52(3):802–803.
32 Piazza M, Ricotta IIJJ, Bower TC, Kaira M, Duncan AA, Cha S, Gloviczki P. Iliac artery stenting combined with open femoral endarterectomy is as effective as open surgical reconstruction for severe iliac and common femoral occlusive disease. Journal of Vascular Surgery. 2011;54(2):402–411.21531527
33 Psacharopulo D, Ferrero E, Ferri M, Viazzo A, Singh Bahia S, Trucco, A, Ricceri F, Nessi F. Increasing efficacy of endovascular recanalization with covered stent graft for TransAtlantic Inter-Society Consensus II D aortoiliac complex occlusion. Journal of Vascular Surgery. 2015;62(5):1219–1226.26391459
34 Reijnen M, van Walraven LA, Fritschy WM, . 1-Year Results of a Multicenter Randomized Controlled Trial Comparing Heparin-Bonded Endoluminal to Femoropopliteal Bypass. JACC Cardiovascular interventions. 2017;10(22):2320–2331.29169500
35 Sachwani GR, Hans SS, Khoury MD, . Results of iliac stenting and aortofemoral grafting for iliac artery occlusions. Journal of vascular surgery. 2013;57(4):1030–1037.23177535
36 Satish M, Walters RW, Aurit SJ, White MD.. Incidence of procedure-specific complications with endovascular vs open bypass repair in PAD patients with type II diabetes. Category: Endovascular and Peripheral Interventions (Including Neurovascular and Carotid). Catheterization and Cardiovascular Interventions. 2018;91 Supplement 2:S93.
37 Secemsky EA, Kennedy K, Schermerhorn M, Landon B, Yeh R. Nationwide readmissions following lower extremity arterial procedures. Journal of the American College of Cardiology. 2017;69(11 Supplement 1):2013.
38 Smolock CJ, Anaya-Ayala JE, Kaufman Y, . Current efficacy of open and endovascular interventions for advanced superficial femoral artery occlusive disease. Journal of vascular surgery. 2013;58(5):1267–1275.e1261-1262.24160311
39 Sussman M, Mallick R, Friedman M, . Failure of surgical and endovascular infrainguinal and iliac procedures in the management of peripheral arterial disease using data from electronic medical records. Journal of vascular and interventional radiology : JVIR. 2013;24(3):378–391, 391.e371–373.23357568
40 Tang L, Paravastu SCV, Thomas SD, Tan E, Farmer E, Varcoe RL. Cost Analysis of Initial Treatment With Endovascular Revascularization, Open Surgery, or Primary Major Amputation in Patients With Peripheral Artery Disease. Journal of endovascular therapy : an official journal of the International Society of Endovascular Specialists. 2018;25(4):504–511.29756521
41 Weis TL, Ruddy JM, Robison JG, Hallett JW, Adams JD. The current risk-benefit outlook for endovascular vs open surgical bifurcated aortoiliac arterial reconstruction therapy for aortoiliac occlusive disease. Annals of Vascular Surgery. 2017;41:16.
42 Zavatta M, Mell MW. A national Vascular Quality Initiative database comparison of hybrid and open repair for aortoiliac-femoral occlusive disease. Journal of vascular surgery. 2018;67(1):199–205.e191.28822655
43 Zhou M, Huang D, Liu C, . Comparison of hybrid procedure and open surgical revascularization for multilevel infrainguinal arterial occlusive disease. Clinical interventions in aging. 2014;9:1595–1603.25284992

## Background/other (n=25)

1 Allie DE, Hebert CJ, Lirtzman MD, Wyatt CH, Keller VA, Khan MH, Khan MA, Fail PS, Vivekananthan K, Mitran EV, Allie SE. Critical limb ischemia: a global epidemic. A critical analysis of current treatment unmasks the clinical and economic costs of CLI. EuroIntervention: journal of EuroPCR in collaboration with the Working Group on Interventional Cardiology of the European Society of Cardiology. 2005 May;1(1):75–84.
2 Beard JD. Should we save critically ischaemic legs at any cost? Acta chirurgica Belgica. 2008;108(6):651–655.19241912
3 Barshes NR, Belkin M. A framework for the evaluation of “value” and cost-effectiveness in the management of critical limb ischemia. Journal of the American College of Surgeons. 2011;213(4):552–566.e555.21943802
4 Conte MS. Discussion. Open surgical revascularization for wound healing: past performance and future directions; and Critical evaluation of endovascular surgery for limb salvage. Plastic and reconstructive surgery. 2011;127: Suppl 1:174s–176s.21200288
5 Cortese B, Granada JF, Scheller B, Schneider PA, Tepe G, Scheinert D, Garcia L< Stabile E, Alfonso F, Ansel G, Zeller T. Drug-coated balloon treatment for lower extremity vascular disease intervention: An international positioning document. European Heart Journal. 2016;37(14):1096–1103.26009594
6 Davies MG, Waldman DL, Pearson TA. Comprehensive endovascular therapy for femoropopliteal arterial atherosclerotic occlusive disease. Journal of the American College of Surgeons. 2005;201(2):275–296.16038827
7 Driver VR, Yao M. Discussion. The economics of limb salvage in diabetes. Plastic and reconstructive surgery. 2011;127: Suppl 1:296s–297s.21200305
8 Eyuboglu M. Clinical outcomes in patients with lower extremity peripheral artery disease undergoing revascularization. American heart journal. 2016;171(1):e5.26699609
9 Hirsch AT. Treatment of peripheral arterial disease - Extending “intervention” to “therapeutic choice". New England Journal of Medicine. 2006;354(18):1944–1947.16672707
10 Hirsch AT, Duval S. Effective vascular therapeutics for critical limb ischemia: a role for registry-based clinical investigation. Circulation Cardiovascular interventions. 2013;6(1):8–11.23424269
11 Houbballah R, Raux M, LaMuraglia G. Part two: against the motion. endovascular therapy is the preferred treatment for patients <65 years old with symptomatic infrainguinal arterial disease. European journal of vascular and endovascular surgery : the official journal of the European Society for Vascular Surgery. 2012;44(2):116–119.
12 Kawada T. In-Hospital Outcomes in Patients With Peripheral Arterial Disease: Comparison of 2 Treatments. The American journal of cardiology. 2016;117(4):701.
13 Klein AJ, Jaff MR, Gray BH Aronow HD Bersin RM … White CJ. SCAI appropriate use criteria for peripheral arterial interventions: An update. Catheterization and Cardiovascular Interventions. 2017;90(4):E90–E110.28489285
14 Lawrence PF. XXXVII.1 minimally invasive techniques for critical limb ischemia surgery. Vascular. 2006;14(SUPPL. 1):S177–S178.
15 Layden J, Michaels J, Bermingham S, Higgins B. Diagnosis and management of lower limb peripheral arterial disease: Summary of NICE guidance. Bmj. 2012;345(7870).
16 Lipsitz EC, Woo K, Rathbun J, Shireman PK. Constructing cost measures for critical limb ischemia. Journal of vascular surgery. 2018;67(5):1627.29685254
17 Looser PMFDN. Thirty-Day Readmissions for Critical Limb Ischemia: Ready for a New Quality Metric? Circulation. 2017;136(2):177–179.28696266
18 Norgren L, Hiatt WR, Dormandy JA, . Inter-Society Consensus for the Management of Peripheral Arterial Disease (TASC II). European journal of vascular and endovascular surgery : the official journal of the European Society for Vascular Surgery. 2007;33: Suppl 1:S1–75.
19 Philip F. 3-Year Outcomes of the OLIVE Registry, a Prospective Multicenter Study of Patients with Critical Limb Ischemia. JACC: Cardiovascular Interventions. 2016;9(2):201–202.26793964
20 Shishehbor MH, Reed GW. Personalized approach to revascularization of critical limb ischemia. Circulation: Cardiovascular Interventions. 2014;7(5):642–644.25336603
21 Siracuse JJ, Farber A. Is Open Vascular Surgery or Endovascular Surgery the Better Option for Lower Extremity Arterial Occlusive Disease? Advances in surgery. 2017;51(1):207–217.28797341
22 Stegman BM, Shishehbor MH. Optimal revascularization for critical limb ischemia: One approach doesn’t always fit all. Journal of Endovascular Therapy. 2015;22(4):482–484.26187972
23 Sterpetti AV. Regarding “Trends in the national outcomes and costs for claudication and limb threatening ischemia: angioplasty vs bypass graft". Journal of vascular surgery. 2012;55(5):1545.
24 Takagi H, Manbe H, Matsui M, Goto SN, Umemoto T. Regarding “Perioperative outcomes and amputation-free survival after lower extremity bypass surgery in California hospitals". Journal of vascular surgery. 2010;52(5):1425–1427; author reply 1427.
25 Woo K, Rathbun J, Lipsitz EC, Shireman PK. Field testing for the critical limb ischemia cost measure. Journal of vascular surgery. 2018;67(6):1933.29801561

## Outcome (n=11)

1 Casella IB, Brochado-Neto FC, Sandri Gde A, . Outcome analysis of infrapopliteal percutaneous transluminal angioplasty and bypass graft surgery with nonreversed saphenous vein for individuals with critical limb ischemia. Vascular and endovascular surgery. 2010;44(8):625–632.20724288
2 Dick F, Diehm N, Galimanis A, Husmann M, Schmidli J, Baumgartner I. Surgical or endovascular revascularization in patients with critical limb ischemia: influence of diabetes mellitus on clinical outcome. Journal of vascular surgery. 2007;45(4):751–761.17306950
3 Garg K, Kaszubski PA, Moridzadeh R, . Endovascular-first approach is not associated with worse amputation-free survival in appropriately selected patients with critical limb ischemia. Journal of vascular surgery. 2014;59(2):392–399.24184092
4 Heller F, Nuiry O, Murgues F, Laroze G, Trombert B, Albertini JN, Favre JP. Economic evaluation of infra-inguinal revascularization for critical lower limb ischemia. Annals of Vascular Surgery. 2014;28(6):1355–1356.
5 Kudo T, Chandra FA, Kwun WH, Haas BT, Ahn SS. Changing pattern of surgical revascularization for critical limb ischemia over 12 years: endovascular vs open bypass surgery. Journal of vascular surgery. 2006;44(2):304–313.16890859
6 Kumar BN, Gambhir RP. Critical limb ischemia-need to look beyond limb salvage. Annals of vascular surgery. 2011;25(7):873–877.21831588
7 Lejay A, Thaveau F, Georg Y, Bajcz C, Kretz JG, Chakfe N. Autonomy following revascularisation in 80-year-old patients with critical limb ischaemia. European journal of vascular and endovascular surgery : the official journal of the European Society for Vascular Surgery. 2012;44(6):562–567; discussion 568.
8 Meltzer AJ, Sedrakyan A, Isaacs A, Connolly PH, Schneider DB. Comparative effectiveness of peripheral vascular intervention versus surgical bypass for critical limb ischemia in the Vascular Study Group of Greater New York. Journal of vascular surgery. 2016;64(5):1320–1326.e1322.27237403
9 Mohapatra A, Henry JC, Avgerinos ED, . Bypass versus endovascular intervention for healing ischemic foot wounds secondary to tibial arterial disease. Journal of vascular surgery. 2018;68(1):168–175.29336904
10 Scali ST, Rzucidlo EM, Bjerke AA, . Long-term results of open and endovascular revascularization of superficial femoral artery occlusive disease. Journal of vascular surgery. 2011;54(3):714–721.21620611
11 Varela C, Acin F, De Haro J, March J, Florez A, Lopez-Quintana A. Influence of surgical or endovascular distal revascularization of the lower limbs on ischemic ulcer healing. The Journal of cardiovascular surgery. 2011;52(3):381–389.21577193

## Comparison (n=9)

1 Banerjee S, Jeon-Slaughter H, Armstrong EJ, . Clinical Outcomes and Cost Comparisons of Stent and Non-Stent Interventions in Infrainguinal Peripheral Artery Disease: Insights From the Excellence in Peripheral Artery Disease (XLPAD) Registry. The Journal of invasive cardiology. 2019;31(1557–2501 (Electronic)):1–9.30611122
2 Baumgartner I. ReoPro and peripheral arterial intervention to improve clinical outcome in patients with Peripheral Arterial Disease (RIO-Trial). ACC Cardiosource Review Journal. 2007;16(10):15–19.
3 Chisci E, Perulli A, Iacoponi F, . Benefit of revascularisation to critical limb ischaemia patients evaluated by a patient-oriented scoring system. European journal of vascular and endovascular surgery : the official journal of the European Society for Vascular Surgery. 2012;43(5):540–547.
4 de Leur K, van Zeeland ML, Ho GH, de Groot HG, Veen EJ, van der Laan L. Treatment for critical lower limb ischemia in elderly patients. World journal of surgery. 2012;36(12):2937–2943.22965534
5 Jorshery SD, Skrip L, Sarac T, Ochoa Chaar CI. Hybrid femoropopliteal procedures are associated with improved perioperative outcomes compared with bypass. Journal of vascular surgery. 2018;68(5):1447–1454.e1445.30360840
6 Ortmann J, Gahl B, Diehm N, Dick F, Traupe T, Baumgartner I. Survival benefits of revascularization in patients with critical limb ischemia and renal insufficiency. Journal of vascular surgery. 2012;56(3):737–745.e731.22677008
7 Pietzsch JB, Weber SA Pietzsch ML, Zeller T. The impact of new endovascular therapies for femoropopliteal arterial disease on therapy utilization and case volumes in Germany, 2009-2013. Value in Health. 2015;18(7):A366.
8 Reynolds S, Galinanes EL, Dombrovskiy VY, Vogel TR. Longitudinal outcomes after tibioperoneal angioplasty alone compared to tibial stenting and atherectomy for critical limb ischemia. Vascular and endovascular surgery. 2013;47(7):507–512.23853224
9 Shah AP, Klein AJ, Sterrett A, . Clinical outcomes using aggressive approach to anatomic screening and endovascular revascularization in a veterans affairs population with critical limb ischemia. Catheterization and cardiovascular interventions : official journal of the Society for Cardiac Angiography & Interventions. 2009;74(1):11–19.19360870

## Systematic review (n=3)

1 Stenting for peripheral artery disease of the lower extremities: An evidence-based analysis. Ontario Health Technology Assessment Series. 2010;10(18):1–88.
2 Biondi-Zoccai G, Sangiorgi G, D’Ascenzo F, . Drug-eluting balloons for peripheral artery disease: a meta-analysis of 7 randomized clinical trials and 643 patients. International journal of cardiology. 2013;168(1):570–571.23462632
3 Almasri J, Adusumalli J, Asi N, . A systematic review and meta-analysis of revascularization outcomes of infrainguinal chronic limb-threatening ischemia. Journal of vascular surgery. 2018;68(2):624–633 29804736

## Sample size <500 (n=2)

1 Steunenberg SL, de Vries J, Raats JW, . Quality of Life and Mortality after Endovascular, Surgical, or Conservative Treatment of Elderly Patients Suffering from Critical Limb Ischemia. Annals of vascular surgery. 2018;51:95–105.29772334
2 Veraldi GF, Mezzetto L, Macri M, Criscenti P, Corvasce A, Poli R. Comparison of Endovascular Versus Bypass Surgery in Femoropopliteal TASC II D Lesions: A Single-Center Study. Annals of vascular surgery. 2018;47:179–187.28943491

## No utilization measure (n=1)

1 Klaphake S, de Leur K, Mulder PGH, . Life Expectancy and Outcome of Different Treatment Strategies for Critical Limb Ischemia in the Elderly Patients. Annals of vascular surgery. 2018;46:241–248.28689942

## Full text unavailable (n=5)

1 Aglialoro A, Patrone M, Ermirio D, Curone PF, Simoni G, Cattaneo A. Revascularization procedure in diabetic patient (surgical, endovascular or both treatment): A 64 months follow-up. Diabetes. 2010.
2 Barshes NR, Chamgers J, Lin PJ, Ozaki CK, Cohen J, Belkin M. The cost-effectiveness of management strategies for critical limb ischemia with tissue loss. Journal of Vascular Surgery. 2011; 54(4): 1229.
3 Fernández Bravo J, Gonzalez Garcia A. Baquero Yebra, Y, Todorova Taneva G, Arribas Diaz A, Aparicio Martinex C. Endovascular treatment with Supera(®) stent vs distal femoropopliteal bypass in femoropopliteal occlusive lesions with P1-P2 segment involvement. Angiologia. 2018;70(3):99–105.
4 Goodney P. Trends in lower extremity surgical and endovascular revascularisation. VASA Zeitschrift fur Gefasskrankheiten. 2011;40(5):343.22010300
5 Sultan S, Hynes N. Mid-term results of subintimal angioplasty for critical limb ischemia 5-year outcomes. Vascular Disease Management. 2011;8(9):E155–E163.

## Lack of sufficient clinical data (n=13)

1 Agarwal S, Sud K, Shishehbor MH. Nationwide Trends of Hospital Admission and Outcomes Among Critical Limb Ischemia Patients: From 2003-2011. Journal of the American College of Cardiology. 2016;67(16):1901–1913.27012780
2 Allie DE, Hebert CJ, Lirtzman MD, . Critical limb ischemia: a global epidemic. A critical analysis of current treatment unmasks the clinical and economic costs of CLI. EuroIntervention. 2005;1(1):75–84.19758881
3 Armstrong EJ, Ryan MP, Baker ER, Martinsen BJ, Kotlarz H, Gunnarsson C. Risk of major amputation or death among patients with critical limb ischemia initially treated with endovascular intervention, surgical bypass, minor amputation, or conservative management. Journal of medical economics. 2017;20(11):1148–1154.28760065
4 Goodney PP, Travis LL, Nallamothu BK, . Variation in the use of lower extremity vascular procedures for critical limb ischemia. Circulation Cardiovascular quality and outcomes. 2012;5(1):94–102.22147886
5 Goodney PP, Taavis LL, Brooke BS, Wallaert JB, DeMartino R, Birkmeyer JD, Goodman DC, Fisher ES. Intensity of vascular care for pad: More spending, but not fewer amputations. Circulation: Cardiovascular Quality and Outcomes. 2012;5(3):2012–2005.
6 Kolte D, Kennedy KF, Shishehbor MH, . Thirty-Day Readmissions After Endovascular or Surgical Therapy for Critical Limb Ischemia: Analysis of the 2013 to 2014 Nationwide Readmissions Databases. Circulation. 2017;136(2):167–176.28465288
7 Masoomi R, Cho J, Hance K, Shah Z, Dawn B, Gupta K. Prevalence predictors and clinical implications of 90-day readmission for patients with critical limb ischemia. Circulation. 2016;134(1):2016–2011.
8 Mustapha JA, Katzen BT, Neville RF, . Determinants of Long-Term Outcomes and Costs in the Management of Critical Limb Ischemia: A Population-Based Cohort Study. Journal of the American Heart Association. 2018;7(16):e009724.30369325
9 Niazi K, Grabner M. Wallace KL. Long-term cost patterns of directional atherectomy vs Other treatment choices for diabetes patients with peripheral artery disease: A 12-month analysis of administrative claims data. Journal of the American College of Cardiology. 2013;62(18 SUPPL. 1):B160.
10 Reinecke H, Unrath M, Freisinger E, . Peripheral arterial disease and critical limb ischaemia: still poor outcomes and lack of guideline adherence. European heart journal. 2015;36(15):932–938.25650396
11 Sachs T, Pomposelli F, Hamdan A, Wyers M, Schermerhorn M. Trends in the national outcomes and costs for claudication and limb threatening ischemia: angioplasty vs bypass graft. Journal of vascular surgery. 2011;54(4):1021–1031.e1021.21880457
12 Vogel TR, Kruse RL. Risk factors for readmission after lower extremity procedures for peripheral artery disease. Journal of vascular surgery. 2013;58(1):90–97.e91-94.23541547
13 Wiseman JT, Fernandes-Taylor S, Saha S, . Endovascular Versus Open Revascularization for Peripheral Arterial Disease. Annals of surgery. 2017;265(2):424–430.28059972