# APPENDIX F Quality Assessment for Included Observational Studies

Author Year | Confounding | Selection bias | Bias in measurement classification of interventions | Bias due to deviations from intended interventions | Bias due to missing data | Bias in measurement of outcomes | Bias in selection of the reported result
Bisdas 2015^23^; Bisdas 2016^24^; Meyer 2016^39^ | Serious: patients; Low: time | Low | Low | Low | Low: in-hospital; Low: 1-year outcomes | Low: in-hospital outcomes; Low: 1-year outcomes | Low
Bodewes 2018^25^ | Serious: patients; Low: time | Moderate | Low | Low | Low | Low | Low
Cejna 2011^31^ | Serious | No information | Low | Low | Moderate: efficacy; Moderate: cost | Low: efficacy outcomes; No info: cost outcomes | Moderate
Darling 2017^26^ | Serious: patients and time | Low | Low | Low | Low: short-term outcomes; Serious: long-term outcomes | Moderate: short-term outcomes; Low: long-term outcomes | Low
Darling 2018a^34^ | Serious: patients; Low: time | Low | Low | Low | Low | Low | Low
Dayama 2019^35^ | Serious: patients; Low: time | Low | Low | Low | Low: short-term outcomes | No info | Low
Dosluoglu 2006^27^ | Serious: patients and time | Low | Low | Low | Low: short-term outcomes; Moderate: long-term outcomes | Low: short-term outcomes; Low: long-term outcomes | Low
Dosluoglu 2012^28^ | Serious: patients and time | Low | Low | Serious | Low: short-term outcomes; Serious: long-term outcomes | Low: short-term outcomes; Low: long-term outcomes | Low
Gargiulo 2011^32^ | No info | Serious | Low | Low | No info | No info | Moderate
Kim 2012^33^ | No info | No info | Low | Low | Moderate: efficacy; Moderate: cost | Low: efficacy; No info: cost outcomes | Moderate
Siracuse 2016^36^ | Serious: patients; Moderate: time | Moderate | Low | Low | Low: short-term outcomes; Serious: long-term outcomes | Low: short-term outcomes; Moderate: long-term outcomes | Low
Taylor 2009^29^ | Serious: patients; Low: time | Moderate | Low | Low | Low | Low | Low
Tsai 2015^30^ | Serious: patients; Low: time | Low | Low | Low | Low: short-term; Moderate: long-term | Low: short-term; Low: mortality) | Low
Werneck 2009^38^ | Serious: patients; Low: time | Low | Low | Low | Low: short-term outcomes & cost | Low: short-term outcomes; Serious: cost | Low