# APPENDIX E Quality Assessment for Included RCT Study

Author Year | Random sequence generation | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessment | Incomplete outcome data | Selective reporting | Other sources of bias
Adam, 2005^2^ | ⚪ | ⚪ | ⚫ | ⚪^*^ | ⚪ | ⚪ | ⚪

⚪ = low risk of bias ⚫ = risk of bias ⯋ = unknown

* low risk of bias for primary outcomes (all-cause mortality and amputation-free survival, but high risk of bias for secondary outcomes