# APPENDIX B Peer Reviewer Comments and Responses

Comment | Response
The comparison to CAD is quite germane and should be expanded a bit further to emphasize the underlying foundational gaps in definitions, disease staging, and endpoints that have plagued evidence based medicine in PAD in general. In CAD, disease staging (both anatomic and functional) is well established and has allowed clinical research including RCTs to provide guidelines relevant to both practitioners and the referring community. The clinical and anatomic spectrum of “CLI” is extremely broad, arguably broader than that of CAD - particularly given the multi-level patterns of arterial occlusive disease as well as the spectrum of limb threat encountered. Accordingly improved disease staging, such as that suggested in the Society for Vascular Surgery Threatened Limb Classification System, will be critical to develop comparative evidence in this field. The optimal approach for ischemic rest pain, minor ulcers without infection, and major tissue loss with infection are likely to be different. | These are great comments and we have made changes to the discussion in response
Similarly, the lack of an integrated anatomic staging system for the limb focused on patterns of disease rather than the lesion-focused lexicon of PAD is another major gap. Effective revascularization in CLI generally requires restoring in-line flow to the ankle and foot; multi-level occlusive disease is the rule rather than the exception. As anatomic pattern of disease is currently a (or possibly the) primary factor driving selection of open versus endovascular treatment, relevant comparisons cannot be made without considering this key element. If one considers the parallel to CAD, any comparison of PCI versus CABG that did not clarify the anatomic context would be considered irrelevant. This critical issue was not addressed in the Discussion. | These are great comments and we have made changes to the discussion in response
Endpoints in PAD/CLI, both clinical and patient-focused, have also lacked consensus. Few would argue with the pre-eminence of mortality and major amputation. However, freedom from recurrent symptoms of CLI and re-interventions are also of great importance to patients. A composite endpoint of freedom from reintervention, recurrent CLI, amputation or death might be the most clinically meaningful. Moreover, from the standpoint of both clinical effectiveness and cost-effectiveness a time-integrated measure would be of greater relevance in a chronic disease like CLI rather than a time-to-first event approach. Please comment on this concept, which may be important for future research in this arena. | These are great comments and we have made changes to the discussion in response
There is inconsistent definition of KQ 2 re limited to CLI or including claudication in different parts of the manuscript | This was edited
You may want to consider the following information and add it to your write-up https://www.ahajournals.org/doi/10.1161/JAHA.118.011245 | This study compared 2 types of endovascular therapy, and there is no surgical therapy comparison, hence it did not meet inclusion criteria. Nevertheless, it is a possible signal of concern about one type of stent.