# APPENDIX A Search Strategy

## Database Searched & Time Period Covered

PubMed – 1/1/2018-1/16/2019

## Language

English

## Search Strategy

peripheral arterial disease[mh] OR critical limb ischemia[mh] OR intermittent claudication[mh] OR critical limb ischemia[tiab] OR critical limb ischemia[ot] OR peripheral artery disease* OR peripheral arterial disease* OR peripheral vascular disease* OR claudication OR limb ischemia or limb threat* OR (ischaemia AND (leg OR legs OR limb OR limbs))

AND

vascular graft* OR amputat* OR blood vessel prosthesis implantation OR endovascular procedure* OR vascular surgical procedure* OR limb salvage OR endovascular OR bypass OR angioplast* OR stent OR stents OR atherectom* OR saphenous vein* OR drug coated balloon*

AND

vascular surgical procedures[MH] OR surgery[tiab] OR surgery[ot] OR surgical[tiab] OR surgical[ot]

AND

"Costs and Cost Analysis"[Mesh] OR “Economics"[Mesh] OR “economics” [Subheading] OR “Cost Savings"[Mesh] OR “Cost-Benefit Analysis"[Mesh] OR “Hospital Costs"[Mesh] OR “Health Expenditures"[Mesh] OR “utilization” [Subheading] OR “Length of Stay"[Mesh] OR “Patient Readmission"[Mesh] OR “Reoperation"[Mesh] OR expensive[tiab] OR cost-effective*[tiab] OR costs[tiab] OR cost[tiab] OR cost-consequence*[tiab] OR cost effective*[tiab] OR economic*[tiab] OR economic-based[tiab] OR cost-saving*[tiab] OR utilization OR “length of stay” OR readmission* OR readmit* OR reoperation* OR re-operation OR “procedure time"

## Database Searched & Time Period Covered

Embase – 1/1/2018-1/17/2019

## Language

English

## Other Limiters

Human

## Search Strategy

(‘critical limb ischemia’/exp OR ‘critical limb ischemia’ OR ‘peripheral occlusive artery disease’/exp OR ‘peripheral occlusive artery disease’ OR ‘intermittent claudication’/exp OR ‘intermittent claudication’ OR (limb NEAR/2 ischemia) OR ((peripheral NEAR/2 artery NEAR/2 disease*):ti,ab,kw) OR ((peripheral NEAR/2 arterial NEAR/2 disease*):ti,ab,kw) OR ((peripheral NEAR/2 vascular NEAR/2 disease*):ti,ab,kw) OR ‘claudication’/exp OR ‘claudication’ OR claudication:ti,ab,kw OR ((limb NEAR/2 threat*):ti,ab,kw) OR ((ischaemia:ti,ab,kw OR ischemi*:ti,ab,kw) AND (leg:ti,ab,kw OR legs:ti,ab,kw OR limb:ti,ab,kw OR limbs:ti,ab,kw)))

AND

((vascular NEAR/2 graft*) OR amputat* OR (blood NEAR/2 vessel NEAR/2 prosthesis NEAR/2 implant*) OR (endovascular NEAR/2 procedure*) OR (limb NEAR/2 salvag*) OR endovascular OR bypass OR angioplast* OR stent OR stents OR atherectom* OR (saphenous NEAR/2 vein*) OR (drug NEAR/2 coated NEAR/2 balloon*))

AND

(‘vascular surgery’/exp OR surgery:ti,ab,kw OR surgical:ti,ab,kw OR (vascular NEAR/2 surgical) OR (vascular NEAR/2 surgery))

AND

(‘cost’/exp OR ‘economics’/exp OR ‘hospital cost’/exp OR ‘health care cost’/exp OR ‘utilization’/exp OR ‘length of stay’/exp OR ‘hospital readmission’/exp OR ‘reoperation’/exp OR ‘cost control’/exp OR ‘cost benefit analysis’/exp OR economic* OR utilization OR ‘length of stay’ OR readmission* OR readmit* OR reoperat* OR ‘re-operation’ OR (procedure NEAR/2 time) OR cost:ti,ab,kw OR costs:ti,ab,kw)

NOTE: ALL RESULTS WERE SEARCHED IN ENDNOTE WITH THE FOLLOWING TERMS TO IDENTIFY POTENTIALLY NON-RELEVANT ARTICLES. RECORDS IDENTIFIED WERE TAGGED AS FILTERED FOR NON-RELEVANCE: