# REFERENCES

1 Olives TD, Nystrom PC, Cole JB, Dodd KW, Ho JD. Intubation of Profoundly Agitated Patients Treated with Prehospital Ketamine. Prehospital Disaster Med. 2016;31(6):593–602. doi:10.1017/S1049023X16000819 27640730
2 Muldowney M, Counts CR, Maider MC, A Comparison of Ketamine to Midazolam for the Management of Acute Behavioral Disturbance in the Out-of-Hospital Setting. Annals of emergency medicine. 2024;(8002646). doi:10.1016/j.annemergmed.2024.09.003
3 Cimino J, Braun C. Clinical Research in Prehospital Care: Current and Future Challenges. Clinics and Practice. 2023;13(5):1266–1285. doi:10.3390/clinpract13050114 37887090
4 Gales A, Maxwell S. Ketamine: Recent Evidence and Current Uses. Anesthesia Tutorial of the Week. Tutorial 381. https://resources.wfsahq.org/wp-content/uploads/Ketamine.pdf
5 Kumar A, Kohli A. Comeback of ketamine: resurfacing facts and dispelling myths. Korean J Anesthesiol. 2021;74(2):103–114. doi:10.4097/kja.20663 33423410
6 Acquisto NM, Mosier JM, Bittner EA, Society of Critical Care Medicine Clinical Practice Guidelines for Rapid Sequence Intubation in the Critically Ill Adult Patient. Critical Care Medicine. 2023;51(10):1411–1430. doi:10.1097/ccm.0000000000006000 37707379
7 Schwenk ES, Viscusi ER, Buvanendran A, Consensus Guidelines on the Use of Intravenous Ketamine Infusions for Acute Pain Management From the American Society of Regional Anesthesia and Pain Medicine, the American Academy of Pain Medicine, and the American Society of Anesthesiologists: Regional Anesthesia and Pain Medicine. Published online June 2018:1. doi:10.1097/AAP.0000000000000806
8 Kupas DF, Wydro GC, Tan DK, Kamin R, Harrell AJ, Wang A. Clinical Care and Restraint of Agitated or Combative Patients by Emergency Medical Services Practitioners. Prehospital Emergency Care. 2021;25(5):721–723. doi:10.1080/10903127.2021.1917736 33877949
9 Morgan MM, Perina DG, Acquisto NM, Ketamine Use in Prehospital and Hospital Treatment of the Acute Trauma Patient: A Joint Position Statement. Prehospital Emergency Care. 2021;25(4):588–592. doi:10.1080/10903127.2020.1801920 32776812
10 Lindbeck G, Shah MI, Braithwaite S, Evidence-Based Guidelines for Prehospital Pain Management: Recommendations. Prehospital Emergency Care. 2023;27(2):144–153. doi:10.1080/10903127.2021.2018073 34928760
11 NASEMSO. National Model EMS Clinical Guidelines. 2022;Version 3.0.
12 VHA Pharmacy Benefits Services, VHA National Emergency Medicine Office. Ketamine for the Management of Acute Pain in VHA Emergency Departments and Urgent Care Centers. National Protocol Guidance. Published online March 2024.
13 VHA Pharmacy Benefits Services, VHA National Emergency Medicine Office. IM Ketamine for Acute Behavioral Agitation in VHA Emergency Departments and Urgent Care Centers. National Protocol Guidance. Published online March 2023.
14 Brown LH, Crowe RP, Pepe PE, Adverse events following emergent prehospital sedation of patients with behavioral emergencies: A retrospective cohort study. Lancet regional health Americas. 2022;9(9918232503006676):100183. doi:10.1016/j.lana.2021.100183 36776280
15 HB21–1251. Appropriate Use of Chemical Restraints On A Person. Published online 2021.
16 Thiessen MEW, Godwin SA, Hatten BW, Clinical Policy: Critical Issues in the Evaluation and Management of Adult Out-of-Hospital or Emergency Department Patients Presenting With Severe Agitation. Annals of Emergency Medicine. 2024;83(1):e1–e30. doi:10.1016/j.annemergmed.2023.09.010 38105109
17 Natoli S. The multiple faces of ketamine in anaesthesia and analgesia. DIC. 2021;10:1–14. doi:10.7573/dic.2020-12-8
18 Aroke EN, Crawford SL, Dungan JR. Pharmacogenetics of Ketamine-Induced Emergence Phenomena: A Pilot Study. Nursing Research. 2017;66(2):105–114. doi:10.1097/nnr.0000000000000197 28252572
19 Kitch BB. Out-of-hospital ketamine: review of a growing trend in patient care. Journal of the American College of Emergency Physicians open. 2020;1(3):183–189. doi:10.1002/emp2.12023 33000033
20 Zeiler FA, Teitelbaum J, West M, Gillman LM. The Ketamine Effect on ICP in Traumatic Brain Injury. Neurocrit Care. 2014;21(1):163–173. doi:10.1007/s12028-013-9950-y 24515638
21 Lipscombe C, Akhlaghi H, Groombridge C, Bernard S, Smith K, Olaussen A. Intubation Rates following Prehospital Administration of Ketamine for Acute Agitation: A Systematic Review and Meta-Analysis. Prehospital emergency care. 2023;27(8):1016–1030. doi:10.1080/10903127.2022.2108178 35913093
22 Yousefifard M, Askarian-Amiri S, Rafiei Alavi SN, The Efficacy of Ketamine Administration in Prehospital Pain Management of Trauma Patients; a Systematic Review and Meta-Analysis. Archives of academic emergency medicine. 2020;8(1):e1.32021982
23 Mankowitz SL, Regenberg P, Kaldan J, Cole JB. Ketamine for Rapid Sedation of Agitated Patients in the Prehospital and Emergency Department Settings: A Systematic Review and Proportional Meta-Analysis. J Emerg Med. 2018;55(5):670–681. doi:10.1016/j.jemermed.2018.07.017 30197153
24 Sobieraj DM, Martinez BK, Miao B, Comparative Effectiveness of Analgesics to Reduce Acute Pain in the Prehospital Setting. Prehospital emergency care. 2020;24(2):163–174. doi:10.1080/10903127.2019.1657213 31476930
25 Greer A, Hewitt M, Khazaneh PT, Ketamine Versus Etomidate for Rapid Sequence Intubation: A Systematic Review and Meta-Analysis of Randomized Trials. Critical Care Medicine. 2025;53(2):e374–e383. doi:10.1097/CCM.0000000000006515 39570063
26 Sterne JAC, Savović J, Page MJ, RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. Published online August 28, 2019:l4898. doi:10.1136/bmj.l4898 31462531
27 Sterne JA, Hernán MA, Reeves BC, ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. Published online October 12, 2016:i4919. doi:10.1136/bmj.i4919 27733354
28 Guyatt G, Oxman AD, Akl EA, GRADE guidelines: 1. Introduction—GRADE evidence profiles and summary of findings tables. Journal of Clinical Epidemiology. 2011;64(4):383–394. doi:10.1016/j.jclinepi.2010.04.026 21195583
29 Fisher AD, Schwartz DS, Petersen CD, Ketamine Administration by Special Operations Medical Personnel During Training Mishaps. Journal of special operations medicine : a peer reviewed journal for SOF medical professionals. 2020;20(3):81–86. doi:10.55460/ERGU-PEZ2
30 Jabourian A, Dong F, Mackey K, Vaezazizi R, Pennington TW, Neeki M. Evaluation of Safety and Efficacy of Prehospital Paramedic Administration of Sub-Dissociative Dose of Ketamine in the Treatment of Trauma-Related Pain in Adult Civilian Population. Cureus. 2020;12(8):e9567. doi:10.7759/cureus.9567 32782893
31 Bebarta VS, Mora AG, Bebarta EK, Prehospital Use of Ketamine in the Combat Setting: A Sub-Analysis of Patients With Head Injuries Evaluated in the Prospective Life Saving Intervention Study. Military medicine. 2020;185(Suppl 1):136–142. doi:10.1093/milmed/usz302 32074369
32 Haske D, Dorau W, Heinemann N, Eppler F, Schopp T, Schempf B. Efficacy and safety in ketamine-guided prehospital analgesia for abdominal pain. Internal and emergency medicine. 2022;17(8):2291–2297. doi:10.1007/s11739-022-03091-w 36205836
33 Randall MM, Raae-Nielsen J, Choi M, Dukes WS, Nesper T, Mesisca MK. Incidence of Dissociation With Low-Dose Pre-hospital Ketamine in Geriatric Patients With Trauma-Related Pain. Cureus. 2022;14(8):e27698. doi:10.7759/cureus.27698 36081959
34 Andolfatto G, Innes K, Dick W, Prehospital Analgesia With Intranasal Ketamine (PAIN-K): a Randomized Double-Blind Trial in Adults. 2019;74(2):241‐250. doi:10.1016/j.annemergmed.2019.01.048
35 Bronsky ES, Koola C, Orlando A, Intravenous Low-Dose Ketamine Provides Greater Pain Control Compared to Fentanyl in a Civilian Prehospital Trauma System: A Propensity Matched Analysis. Prehosp Emerg Care. 2019;23(1):1–8. doi:10.1080/10903127.2018.1469704 29775117
36 Cohen B, Talmy T, Gelikas S, Opioid sparing effect of ketamine in military prehospital pain management-A retrospective study. The journal of trauma and acute care surgery. 2022;93(2S Suppl 1):S71–S77. doi:10.1097/TA.0000000000003695 35583978
37 Galinski M, Dolveck F, Combes X, Management of severe acute pain in emergency settings: ketamine reduces morphine consumption. Am J Emerg Med. 2007;25(4):385–390. doi:10.1016/j.ajem.2006.11.016 17499654
38 Jennings PA, Cameron P, Bernard S, Morphine and ketamine is superior to morphine alone for out-of-hospital trauma analgesia: A randomized controlled trial. Ann Emerg Med. 2012;59(6):497–503. doi:10.1016/j.annemergmed.2011.11.012 22243959
39 Johansson P, Kongstad P, Johansson A. The effect of combined treatment with morphine sulphate and low-dose ketamine in a prehospital setting. Scand J Trauma Resusc Emerg Med. 2009;17(1). doi:10.1186/1757-7241-17-61
40 Le Cornec C, Le Pottier M, Broch H, Ketamine Compared With Morphine for Out-of-Hospital Analgesia for Patients With Traumatic Pain: A Randomized Clinical Trial. JAMA network open. 2024;7(1):e2352844. doi:10.1001/jamanetworkopen.2023.52844 38285446
41 McArthur R, Cash RE, Anderson J, Fentanyl versus nebulized ketamine for prehospital analgesia: A retrospective data review. The American journal of emergency medicine. 2025;89(aa2, 8309942):124–128. doi:10.1016/j.ajem.2024.12.033 39708459
42 McMullan JT, Droege CA, Chard KM, Out-of-Hospital Intranasal Ketamine as an Adjunct to Fentanyl for the Treatment of Acute Traumatic Pain: A Randomized Clinical Trial. Annals of emergency medicine. 2024;84(4):363–373. doi:10.1016/j.annemergmed.2024.04.018 38864781
43 Melcer T, Walker GJ, Dye JL, Is Prehospital Ketamine Associated with a Change in the Prognosis of PTSD? Mil Med. 2023;188(7–8):E2165–E2174. doi:10.1093/milmed/usac014
44 Smyth MA, Noordali H, Starr K, Paramedic analgesia comparing ketamine and morphine in trauma (PACKMaN): a randomised, double-blind, phase 3 trial. The Lancet regional health Europe. 2025;53:101265. doi:10.1016/j.lanepe.2025.101265 40247853
45 Torres AC, Bebarta VS, April MD, Ketamine Administration in Prehospital Combat Injured Patients With Traumatic Brain Injury: A 10-Year Report of Survival. Cureus. 2020;12(7):e9248. doi:10.7759/cureus.9248 32821594
46 Wiel E, Zitouni D, Assez N, Continuous infusion of ketamine for out-of-hospital isolated orthopedic injuries secondary to trauma: A randomized controlled trial. Prehosp Emerg Care. 2015;19(1):10–16. doi:10.3109/10903127.2014.923076 24932670
47 Tomasino S, Trillo G, Tullio A, Prehospital drugs for sedation in psychomotor agitation, friends or foes? An observational retrospective study. Signa Vitae. 2023;19(6):160–167. doi:10.22514/sv.2023.110
48 Cunningham C, Gross K, Broach JP, O’Connor L. Patient Outcomes Following Ketamine Administration for Acute Agitation with a Decreased Dosing Protocol in the Prehospital Setting. Prehospital and disaster medicine. 2021;36(3):276–282. doi:10.1017/S1049023X21000236 33678204
49 Sergot PB, Mead LB, Jones EB, Crowe RP, Huebinger RM. Association of Ketamine Dosing with Intubation and Other Adverse Events in Patients with Behavioral Emergencies. Prehospital emergency care. 2024;28(6):851–856. doi:10.1080/10903127.2023.2234491 37418327
50 Burnett AM, Peterson BK, Stellpflug SJ, The association between ketamine given for prehospital chemical restraint with intubation and hospital admission. Am J Emerg Med. 2015;33(1):76–79. doi:10.1016/j.ajem.2014.10.016 25455046
51 Coffey SK, Vakkalanka JP, Egan H, Outcomes Associated with Lower Doses of Ketamine by Emergency Medical Services for Profound Agitation. The western journal of emergency medicine. 2021;22(5):1183–1189. doi:10.5811/westjem.2021.5.50845 34546896
52 Cole JB, Moore JC, Nystrom PC, A prospective study of ketamine versus haloperidol for severe prehospital agitation. Clin Toxicol. 2016;54(7):556–562. doi:10.1080/15563650.2016.1177652
53 Cole JB, Klein LR, Nystrom PC, A prospective study of ketamine as primary therapy for prehospital profound agitation. Am J Emerg Med. 2018;36(5):789–796. doi:10.1016/j.ajem.2017.10.022 29033344
54 Friedman MS, Saloum D, Haaland A, Drapkin J, Likourezos A, Strayer RJ. Description of Adverse Events in a Cohort of Dance Festival Attendees with Stimulant-Induced Severe Agitation Treated with Dissociative-Dose Ketamine. Prehospital emergency care. 2021;25(6):761–767. doi:10.1080/10903127.2020.1837311 33054495
55 Gangathimmaiah V, Le Cong M, Wilson M, Ketamine Sedation for Patients With Acute Behavioral Disturbance During Aeromedical Retrieval: A Retrospective Chart Review. Air Med J. 2017;36(6):311–314. doi:10.1016/j.amj.2017.06.004 29132594
56 Helmer J, Acker J, Deakin J, Johnston T. Canadian paramedic experience with intramuscular ketamine for extreme agitation: A quality improvement initiative. Australasian Journal of Paramedicine. 2020;17:1–9. doi:10.33151/ajp.17.763
57 Holland D, Glober N, Christopher S, Zahn E, Lardaro T, O’Donnell D. Prehospital sedation with ketamine vs. midazolam: Repeat sedation, intubation, and hospital outcomes. The American journal of emergency medicine. 2020;38(9):1748–1753. doi:10.1016/j.ajem.2020.05.011 32738471
58 Isoardi KZ, Parker LE, Page CB, Ketamine as a rescue treatment for severe acute behavioural disturbance : A prospective prehospital study. Emergency medicine Australasia: EMA. 2021;33(4):610–614. doi:10.1111/1742-6723.13682 33202484
59 Keseg D, Cortez E, Rund D, Caterino J. The use of prehospital ketamine for control of agitation in a metropolitan firefighter-based EMS system. Prehosp Emerg Care. 2015;19(1):110–115. doi:10.3109/10903127.2014.942478 25153713
60 Lebin JA, Akhavan AR, Hippe DS, Psychiatric Outcomes of Patients With Severe Agitation Following Administration of Prehospital Ketamine. Academic Emergency Medicine. 2019;26(8):889–896. doi:10.1111/acem.13725 30873690
61 Melamed E, Oron Y, Ben-Avraham R, Blumenfeld A, Lin G. The combative multitrauma patient: A protocol for prehospital management. Eur J Emerg Med. 2007;14(5):265–268. doi:10.1097/MEJ.0b013e32823a3c9b 17823561
62 O’Brien MC, Kelleran KJ, Burnett SJ, Fixed dose ketamine for prehospital management of hyperactive delirium with severe agitation. The American journal of emergency medicine. 2024;81(aa2, 8309942):10–15. doi:10.1016/j.ajem.2024.04.011 38626643
63 O’Connor L, Rebesco M, Robinson C, Outcomes of Prehospital Chemical Sedation With Ketamine Versus Haloperidol and Benzodiazepine or Physical Restraint Only. Prehosp Emerg Care. 2019;23(2):201–209. doi:10.1080/10903127.2018.1501445 30118360
64 Parks DJ, Alter SM, Shih RD, Solano JJ, Hughes PG, Clayton LM. Rescue Intubation in the Emergency Department After Prehospital Ketamine Administration for Agitation. Prehospital and disaster medicine. 2020;35(6):651–655. doi:10.1017/S1049023X20001168 32921342
65 Scheppke KA, Braghiroli J, Shalaby M, Chait R. Prehospital use of im ketamine for sedation of violent and agitated patients. West J Emerg Med. 2014;15(7):736–741. doi:10.5811/westjem.2014.9.23229 25493111
66 Shahtahmasebi R, Johnson R, Shahtahmasebi S. Impact of a ketamine sedation protocol on intubation rates and undesirable outcomes in the transport of patients with acute behavioural disturbance. Emergency medicine Australasia : EMA. 2020;32(1):100–104. doi:10.1111/1742-6723.13368 31379109
67 Solano JJ, Clayton LM, Parks DJ, Prehospital Ketamine Administration for Excited Delirium with Illicit Substance Co-Ingestion and Subsequent Intubation in the Emergency Department. Prehospital and disaster medicine. 2021;36(6):697–701. doi:10.1017/S1049023X21000935 34551849
68 Kunkel S, Lenz T. Hemodynamics in Helicopter Emergency Medical Services (HEMS) Patients Undergoing Rapid Sequence Intubation With Etomidate or Ketamine. The Journal of emergency medicine. 2022;62(2):163–170. doi:10.1016/j.jemermed.2021.10.004 35031173
69 Asberry C, Martini A. The Effect of Full-Dose Versus Half-Dose Ketamine for Induction During Rapid Sequence Intubation on Patient Outcomes. Critical care nursing quarterly. 2024;47(2):163–169. doi:10.1097/CNQ.0000000000000507 38419180
70 Stanke L, Nakajima S, Zimmerman LH, Collopy K, Fales C, Powers W 4th. Hemodynamic Effects of Ketamine Versus Etomidate for Prehospital Rapid Sequence Intubation. Air medical journal. 2021;40(5):312–316. doi:10.1016/j.amj.2021.05.009 34535237
71 Krebs W, Werman H, Jackson J, Prehospital Ketamine Use for Rapid Sequence Intubation: Are Higher Doses Associated With Adverse Events?. Air medical journal. 2021;40(1):36–40. doi:10.1016/j.amj.2020.11.007 33455623
72 Peters AJ, Khan SA, Koike S, Rowell S, Schreiber M. Outcomes and physiologic responses associated with ketamine administration after traumatic brain injury in the United States and Canada: a retrospective analysis. Journal of trauma and injury. 2023;36(4):354–361. doi:10.20408/jti.2023.0034 39381569
73 April MD, Bridwell RE, Davis WT, Interventions associated with survival after prehospital intubation in the deployed combat setting. The American journal of emergency medicine. 2024;79(aa2, 8309942):79–84. doi:10.1016/j.ajem.2024.01.047 38401229
74 Bredmose PP, Lockey DJ, Grier G, Watts B, Davies G. Pre-hospital use of ketamine for analgesia and procedural sedation. Emergency medicine journal : EMJ. 2009;26(1):62–64. doi:10.1136/emj.2007.052753 19104109
75 Mansvelder FJ, Bossers SM, Loer SA, Etomidate versus Ketamine as Prehospital Induction Agent in Patients with Suspected Severe Traumatic Brain Injury. Anesthesiology. 2024;140(4):742–751. doi:10.1097/ALN.0000000000004894 38190220
76 Qureshi R, Mayo-Wilson E, Li T. Harms in Systematic Reviews Paper 1: An introduction to research on harms. Journal of Clinical Epidemiology. 2022;143:186–196. doi:10.1016/j.jclinepi.2021.10.023 34742788
77 Qureshi R, Naaman K, Quan NG, Development and Evaluation of a Framework for Identifying and Addressing Spin for Harms in Systematic Reviews of Interventions. Ann Intern Med. 2024;177(8):1089–1098. doi:10.7326/m24–0771 39008854
78 Palamar JJ, Jewell JS, El-Shahawy O, Black JC. Trends in poisonings involving ketamine in the United States, 2019–2023. Drug and Alcohol Dependence. 2025;268:112549. doi:10.1016/j.drugalcdep.2025.112549 39827824
79 Yang KH, Kepner W, Cleland CM, Palamar JJ. Trends and characteristics in ketamine use among US adults with and without depression, 2015–2022. Journal of Affective Disorders. 2025;373:345–352. doi:10.1016/j.jad.2024.12.108 39746553
80 Palamar JJ. Trends in ketamine use among nightclub attendees in New York City, 2017–2024. International Journal of Drug Policy. 2025;140:104825. doi:10.1016/j.drugpo.2025.104825 40319543