# ACKNOWLEDGMENTS

The authors are grateful to Becky Baltich Nelson, MLIS, MS for literature searching, data abstraction efforts, and citation management support, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Douglas Villard, MD
  Director of Emergency Ambulance Services
  National Emergency Medicine Office