# DISCUSSION

The aim of this systematic review was to synthesize evidence on the safety of ketamine administration for acute pain, sedation, and RSI in the prehospital setting to inform national protocols for VHA paramedics and EMTs.

Evidence regarding mortality following ketamine administration in the prehospital setting is limited to 3 retrospective cohorts (1 in which ketamine was used for acute pain, 1 in which ketamine was used for sedation, and 1 study in which the indication for ketamine was not reported).^2,45,72^ None of these 3 studies found a significant difference in mortality between patients receiving ketamine compared to other medications given for the same indication. However, the small number of studies, small sample sizes with limited power to detect differences in mortality, and variability across studies in patient populations, indications for ketamine, co-interventions and comparator medications, and mortality outcomes (eg, survival to hospital discharge vs mortality within 6-months of injury) prevents conclusions from being drawn regarding mortality risk with prehospital administration of ketamine. This evidence should be considered preliminary.

While we did not formally include studies of esketamine, an enantiomer of ketamine with distinct pharmacologic properties that is used widely by EMS personnel in Europe, it is worth noting that a retrospective cohort^75^ from the Netherlands of 1,451 patients with suspected severe TBI undergoing RSI from air medical services did not find a significant difference in 30-day mortality with etomidate compared to esketamine for RSI (32.9% etomidate vs 33.8% esketamine; adjusted OR = 1.08, 95% CI [0.67, 1.73]). Overall mortality rates were high in this study (32%–34%), likely owing to the severe nature of patients’ injuries requiring air medical transport and RSI.

Among studies of prehospital ketamine administration for acute pain or sedation, the incidence of serious adverse events was generally low and did not significantly differ between ketamine and comparator medications. Two RCTs^42,44^ comparing ketamine to morphine or as an adjunct to fentanyl compared to placebo for acute pain management in the prehospital setting reported low rates (0–3%) of serious adverse events overall (a composite outcome commonly including cardiac arrest, invasive airway placement, or severe oxygen desaturation) with no differences based on receipt of ketamine. Similarly, 2 retrospective cohorts,^2,14^ including 1 large cohort (N = 7,973), of patients with acute behavioral disturbance comparing ketamine to benzodiazepines or antipsychotics for sedation found that rates of cardiac arrest were low overall (0.1% to 2%) and did not significantly differ between groups.

The large cohort^14^ (N = 7,973) of patients requiring sedation for acute behavioral disturbance found that receipt of ketamine was associated with an increased incidence of invasive airway placement, which was the most frequent serious adverse event reported in this study. However, 2 smaller cohorts^1,2^ of patients requiring sedation for acute behavioral disturbance or agitation did not find that receipt of ketamine was associated with higher intubation incidence. Several study authors discussed the subjective nature of decisions to intubate, which may be informed by multiple factors including a provider’s personal practice, comfort treating patients in a dissociated state, and resources available to monitor a potentially unstable patient.^1,50^ When considered in this context, intubation rates may not directly reflect ketamine safety. Nonetheless, given that existing evidence is inconsistent, further research is needed to clarify the potential increased risk of intubation when ketamine is used for sedation in the prehospital setting.

Studies of ketamine for acute pain management in the prehospital setting, which accounted for nearly half of prioritized studies overall, provide the most informative evidence regarding the incidence of non-serious adverse events. Overall, these studies found that compared to opioids or placebo, ketamine may be associated with a higher incidence of neuropsychological effects, sedation, dizziness, visual disturbance, and emergence phenomenon. Nausea and vomiting, dizziness, disorientation, and hallucinations were among the most common non-serious adverse events reported overall.

Only 2 retrospective cohorts^68,70^ evaluated the risk of hypotension with ketamine for RSI compared to etomidate in the prehospital setting and had inconsistent results. Relative to studies of prehospital ketamine for acute pain and sedation, the safety of ketamine for RSI in the prehospital setting has been less frequently studied and represents an important area for future research.

Across studies, doses of ketamine ranged from 0.1–0.2 mg/kg IV and 0.5–1 mg/kg IN for pain control, 1–5 mg/kg IM for sedation, and 1–2 mg/kg IV for RSI. Two retrospective cohorts compared adverse event incidence with different dosages of ketamine in patients requiring sedation for acute behavioral disturbance in the prehospital setting. One of these cohorts^49^ found that higher dose ketamine was associated with a higher incidence of intubation, but the same finding was not observed in the second cohort.^48^ Neither study found that higher ketamine doses were associated with a higher incidence of other adverse events. In 2 cohorts comparing different ketamine doses among patients who required RSI, 1 cohort^71^ found that high dose (> 2 mg/kg IV) ketamine was associated with a higher incidence of hypotension, bradycardia, oxygen desaturation, laryngospasm, and agitation but not vomiting, hypertension, cardiac arrest, or tachycardia. The other cohort^69^ compared a lower dose of ketamine (1 mg/kg IV/IO) to standard dose ketamine (2 mg/kg IV/IO) for RSI and reported no differences in peri-intubation cardiac arrest incidence. The applicability of these findings is unclear given that protocols for prehospital ketamine may specify standard weight-based ketamine dosing for sedation or RSI that are lower than the “high dose” ketamine used in some of these studies. However, the trend towards potentially higher rates of some adverse events with higher ketamine doses warrants consideration by EMS personnel, who must often estimate patient weight and could be at risk of administering a higher dose than intended.

Ketamine appears to be at least as effective as other medications commonly used for acute pain management, sedation for acute behavioral disturbance, and RSI in the prehospital setting. Ketamine resulted in similar or higher levels of pain relief compared to opioids or fentanyl in patients requiring prehospital acute pain management. Likewise, prehospital ketamine was more or similarly effective for sedation and RSI, although fewer studies reported effectiveness outcomes for these indications. While studies have evaluated the potential risks associated with higher ketamine doses, as discussed above, less is known about the lowest effective ketamine doses for certain indications, such as sedation. Establishing the lower threshold of effective ketamine doses for acute pain, sedation, and RSI in the prehospital setting represents another area for future research.

## LIMITATIONS

Although we identified a large body of evidence evaluating prehospital ketamine administration, studies varied widely in terms of the indication for ketamine, comparators and co-interventions, and outcomes assessed, making it difficult to draw strong conclusions regarding ketamine’s safety for a specific indication. Additionally, half of the included studies lacked a comparison group or did not adequately control for baseline differences between intervention groups, limiting our ability to understand whether benefits and harms differed based on receiving ketamine or could be explained by other factors. Conducting research in the prehospital setting is inherently challenging due to patient acuity, limited resources, and unpredictable care environments, as well as the challenge of systematically integrating data from different points along the patient’s course from prehospital care, the ED, and the hospital. However, there is a growing interest in conducting research in this field, which is reflected in the observation that more than half of studies included in this review were published within the last 5 years. Recent innovations in mobile health technologies, providing tools for linking and transmitting patient data to hospitals, may improve the feasibility of research in this field.^3^

Most systematic reviews focus on the benefits of interventions, and systematically synthesizing the harms of an intervention presents some unique challenges. Published clinical trials and observational studies of interventions often lack systematic and/or detailed reporting of harms, limiting the information available to systematic reviewers.^76^ Systematic reviewers must also attempt to discern selective reporting of harms or “spin” in the way studies present harms data.^77^ In this review, we focused on a thorough synthesis of harms, including consideration of heterogeneity in reporting of harms data across studies and overall study risk of bias. However, our synthesis was still limited by our reliance on the information available in published studies.

## FUTURE RESEARCH

Although there is a large volume of literature on this topic, existing evidence still has some important gaps. Across all studies of ketamine used for different indications in the prehospital setting, mortality data are scant. Future research powered to detect differences in mortality and cardiac arrest rates would help to further establish ketamine as a safe option for prehospital use. Because patient deaths and cardiac arrests are rare events, large-scale database studies, such as those conducted within VHA, may be best suited to evaluate these outcomes. Additionally, future research could help to clarify the risk of adverse events when ketamine is used for sedation in cases of acute behavioral disturbance, specifically whether ketamine used for this indication is associated with an increased incidence of intubation or severe oxygen desaturation. The most informative studies to address this question would be RCTs or cohort studies that adjust for baseline differences between groups. Similarly, further comparative evidence examining ketamine for acute pain management in the prehospital setting would help to confirm the incidence of visual disturbance and emergence phenomena.

Compared to studies of ketamine for acute pain and sedation, fewer studies have evaluated ketamine used for RSI in the prehospital setting. Future research for this indication would help to determine whether there is any difference in risk of hypotension and other adverse effects with ketamine compared to etomidate. Given the higher potential for adverse events with higher doses of ketamine, future research could also help determine the lower thresholds of effective ketamine dosing for acute pain, sedation, and RSI in the prehospital setting. Other future research considerations include identifying best practices to accurately assess patient weight in the prehospital setting and evaluation of implementation efforts to ensure that existing protocols regarding ketamine dosing are followed.

Finally, recreational use of ketamine is increasing based on survey data and poisonings reported to US Poison Centers,^78–80^ and it is unclear how a higher prevalence of ketamine use in the population may impact management decision or outcomes when ketamine is used in the prehospital setting, particularly in cases of undifferentiated acute behavioral disturbance or agitation.

## CONCLUSIONS

Ketamine has been broadly incorporated into national and state EMS protocols for the management of patients with urgent and emergent conditions and has a long history of use as a medication for procedural sedation and anesthesia in the hospital setting. Overall, based on existing evidence, ketamine does not appear to increase the risk of serious adverse effects compared to other medications used for acute pain management, sedation, and RSI in the prehospital setting, with the exception of a potentially higher rate of intubation or severe oxygen desaturation when ketamine is used for acute behavioral disturbance compared to benzodiazepines or antipsychotics. However, the evidence is limited by study methodological weaknesses, variability in co-interventions and comparators, and differences in how harms were reported across studies. Evidence on mortality was limited to 3 retrospective cohorts with varying patient populations, comparators, and outcome definitions and should be considered preliminary. Future research could help to address current evidence gaps. Large database studies could help to confirm that prehospital administration of ketamine is associated with a relatively low risk of mortality or cardiac arrest (rare events overall) compared to alternative medications. RCTs or well-designed cohort studies would provide further insight into the potential risks of ketamine for sedation in cases of acute behavioral disturbance.