# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Supplementary Materials.

Literature flow diagram summarizing results of study selection process.

## OVERVIEW OF INCLUDED STUDIES

Our search identified 1,652 potentially relevant articles after deduplication. Of these, 49 studies met eligibility criteria: 18 studies of ketamine for acute pain management,^29–46^ 24 studies of ketamine as a sedative for patients with acute behavioral disturbance or agitation,^1,2,14,47–67^ 4 studies of ketamine for RSI,^68–71^ and 3 studies of ketamine that did not specify an indication.^72–74^ We also identified 4 underway studies: 3 RCTs examining ketamine for pain and 1 RCT examining ketamine for sedation (see Supplementary Materials).

We prioritized synthesis of 24 studies^1,2,14,34–49,68–72^ as the most rigorous and potentially informative evidence: 8 RCTs and 16 retrospective cohorts. Most of the prioritized cohort studies adjusted for baseline differences between groups but when this more reliable evidence was not available (as in the case of studies comparing different dosages of ketamine), we described findings from retrospective cohorts that did not adjust for baseline group differences. Characteristics of the prioritized studies are shown in Table 1. The studies that we did not prioritize either lacked a comparison group or did not employ methods to account for baseline differences between groups (ie, control for potential confounding), making it difficult to assess ketamine’s effects.

In most of the 24 prioritized studies, ketamine was administered by EMS personnel from ambulance services. Exceptions were 2 studies^43,45^ in which ketamine was administered for acute pain in US military combat settings and 4 studies^68–71^ in which ketamine was given by air medical transport service personnel for RSI. Ketamine was usually given IV or IM and doses ranged from 0.2 to 2 mg/kg IV or 1 to 5 mg/kg IM, depending on the indication. In studies of ketamine for pain, the comparator was most often an opioid medication. In studies of ketamine for sedation, the comparator was most often a benzodiazepine, and in studies of ketamine for RSI, the comparator was usually etomidate. Four studies^48,49,69,71^ compared different doses of ketamine. Notably, in studies of acute pain management or treatment of acute behavioral disturbance, patients often received more than 1 medication (eg, ketamine and an opioid). Studies used different methods to evaluate the effects of ketamine in these cases, often by assessing outcomes according to whether ketamine was the first medication administered.

Most studies only evaluated adverse events that occurred in the short-term (ie, within hours or days of receiving ketamine). Several studies examined composite outcomes of “any adverse event” or “any serious adverse event.” Otherwise, we categorized adverse events as gastrointestinal (nausea, vomiting, etc), cardiac (hypotension, cardiac arrest, arrythmias, etc), respiratory (desaturation, pneumonia, aspiration, intubation, advanced airway management, etc), mental health/behavioral (emergence reaction, hallucinations, agitation, etc), and other (allergic reactions, dizziness, headache, visual disturbance, itching, etc). Effectiveness outcomes included measures of pain intensity, opioid requirements, need for additional sedation, intubation success, and ED or hospital length of stay. Relatively few studies evaluated mortality.

Several RCTs did not blind participants or providers to the intervention, a methodological limitation that may have biased self-reported outcomes. Several retrospective cohorts did not report information regarding co-interventions, which may have skewed outcome results, and some did not adjust for baseline differences between groups for all outcomes of interest. Detailed risk of bias assessments for prioritized studies are available in the Supplementary Materials.

Table 1 Key Characteristics of RCTs and Controlled Observational Studies (Prioritized Studies)

Study | Study Design; Sample Size | Ketamine Indication | Population | Ketamine Details | Comparator | Outcomes Assessed
Andolfatto 2019^34^ | RCT; N=120 | Pain | Adult patients with pain requiring analgesia | 0.5–1mg/kg IN to both nostrils + nitrous oxide | Placebo^a^ + nitrous oxide | GI AEs, Any AEs, Mental/Behavioral AEs, Pain reduction
Bronsky 2019^35^ | RC; N=200 | Pain | Adult patients with severe pain | 0.3 mg/kg IV every 20 min. (3 dose max) | Fentanyl | Cardiac AEs, Respiratory AEs, Any AEs, Pain reduction, Pain medication requirements
Cohen 2022^36^ | RC; N=382 | Pain | Trauma casualties (16+) with severe pain | Mean: 29 mg IV | Opioids alone | Pain reduction, Pain medication requirements
Galinski 2007^37^ | RCT; N=73 | Pain | Adult patients presenting with trauma and severe acute pain | 0.2 mg/kg IV over 10 min. + morphine | Placebo^a^ + morphine | GI AEs, Respiratory AEs, Other AEs, Mental/Behavioral AEs, Pain reduction, Morphine requirements
Jennings 2012^38^ | RCT; N=135 | Pain | Adult patients with moderate to severe traumatic pain | 10–20 mg initial bolus IV + 10 mg every 3 min. + morphine | Morphine alone | GI AEs, Cardiac AEs, Other AEs, Any AEs, Mental/Behavioral AEs, Pain reduction
Johansson 2009^39^ | RCT; N=27 | Pain | Patients with bone fractures receiving morphine sulfate | 0.2 mg/kg IV until NRS score below 4 + morphine | Morphine alone | GI AEs, Mental/Behavioral AEs, Pain reduction
Le Cornec 2024^40^ | RCT; N=251 | Pain | Adult patients with traumatic pain | 20 mg IV over 2 min. + 10 mg every 10 min. | Morphine | GI AEs, Cardiac AEs, Other AEs, Any AEs, Mental/Behavioral AEs, Pain reduction, Morphine requirements
McArthur 2025^41^ | RC; N=1480 | Pain | Adult patients with pain | 1 mg/kg via breath-actuated nebulizer | Fentanyl | Pain reduction
McMullan 2024^42^ | RCT; N=199 | Pain | Adult males with acute traumatic injuries requiring analgesia | 50 mg IN + fentanyl | Placebo^a^ + fentanyl | GI AEs, Respiratory AEs, Other AEs, Any AEs, Any serious AEs, Mental/Behavioral AEs, Pain reduction, Morphine requirements
Melcer 2023^43^ | RC; N=202 | Pain | US combat casualties with serious injury in Iraq or Afghanistan | Mean: 70.4 mg IV or IM during first 6 hours post-injury | Opioids | PTSD Diagnosis
Smyth 2025^44^ | RCT; N=449 | Pain | Patients (16+) with severe pain following traumatic injury | 10 ml of 1mg/ml IV or IO over 5 min.; second dose given as needed (20 mg max) | Morphine | GI AEs, Cardiac AEs, Respiratory AEs, Other AEs, Any AEs, Any serious AEs, Mental/Behavioral AEs, ED LOS, Hospital/ICU admission
Torres 2020^45^ | RC; N=4183 | Pain | US combat casualties with head trauma | NR | No KET exposure | Survival to hospital discharge, Time to death
Wiel 2015^46^ | RCT; N=66 | Pain | Adult patients with orthopedic injuries secondary to trauma with severe acute pain | 0.2 mg/kg initial bolus IV + continuous infusion IV at 0.2 mg/kg/hr + morphine | Placebo^a^ + morphine | GI AEs, Mental/Behavioral AEs, Pain reduction, Morphine requirements
Brown 2022^14^ | RC; N=7973 | Sedation: behavioral disturbance | Patients (15+) presenting with a behavioral emergency | IM (dose NR) | Benzodiazepine, antipsychotic | Cardiac AEs, Respiratory AEs, Any serious AEs, Any AE, Need for additional sedation
Cunningham 2021^48^ | RC; N=292 | Sedation: agitation | Adult patients with acute agitation or agitated delirium | High dose (3 mg/kg IM + 1 mg/kg IM if needed) | Standard dose (4 mg/kg IM) | Respiratory AEs, Any AE, Staff injury, Additional restraint, Hospital admission, ED LOS
Muldowney 2024^2^ | RC; N=376 | Sedation: behavioral disturbance | Adult patients with acute behavioral disturbance | 5 mg/kg IV or IM up to a max. of 500 mg | Benzodiazepine: Midazolam | Cardiac AEs, Respiratory AEs, Mortality, Need for additional sedatives, Hospital or ICU admission, Hospital LOS
Olives 2016^1^ | RC; N=135 | Sedation: agitation | Adult patients with agitation | 5 mg/kg IM or 2 mg/kg IV | Benzodiazepines: Midazolam, Haloperidol | Intubation
Sergot 2024^49^ | RC; N=2383 | Sedation: behavioral disturbance | Adult patients with behavioral concerns | High dose (> 2 mg/kg IV or IO or 5 mg/kg IM) | Standard dose (≤ 2 mg/kg IV or IO or 5 mg/kg IM) | Cardiac AEs, Respiratory AEs, Improvement in agitation, Need for additional sedation
Tomasino 2023^47^ | RC; N=319 | Sedation: agitation | Adult patients with agitation and aggressive behavior | Mean: 94.6 mg IV; 101.1 mg IM | Benzodiazepine: Midazolam, Diazepam | Respiratory AEs, Hospital LOS
Asberry 2024^69^ | RC; N=212 | RSI | Adult patients undergoing prehospital RSI | Low dose (1 mg/kg IV or IO) | Full-dose KET (2 mg/kg IV) | Peri-intubation cardiac arrest
Krebs 2021^71^ | RC; N=130 | RSI | Adult patients intubated by EMS or air medical services | High dose (> 2 mg/kg IV) | Standard dose (≤ 2 mg/kg IV) | GI AEs, Cardiac AEs, Respiratory AEs, Mental/Behavioral AEs, Successful intubation
Kunkel 2022^68^ | RC; N=306 | RSI | Adult patients intubated by air medical transport | 1 mg/kg or 2 mg/kg, (admin. method NR) | Etomidate | Respiratory AEs
Stanke 2021^70^ | RC; N=113 | RSI | Adult critically ill patients undergoing RSI | 1.5–2 mg/kg IV | Etomidate | Cardiac AEs, First pass intubation success
Peters 2023^72^ | RC; N=841 | Any | Patients (15+) with moderate to severe TBI | NR | No KET exposure | Cardiac AEs, Respiratory AEs, Other AEs, Death within 6 months of injury

Notes.

a Studies utilizing a placebo control group provided another pain medication to all patients (eg, ketamine + morphine vs placebo + morphine).

Abbreviations. AEs=adverse events; ED=emergency department; EMS=emergency medical services; HR=hour; ICU=intensive care unit; IM=intramuscular; IN=intranasal; IO=intraosseous; IV=intravenous; KET=ketamine; kg=kilogram; LOS=length of stay; mg=milligram; NR=not reported; RC=retrospective cohort; TBI=traumatic brain injury.

## ACUTE PAIN MANAGEMENT

### Safety of Prehospital Ketamine for Acute Pain Management

A single retrospective cohort^45^ of 4,183 US combat casualties with head trauma from the Department of Defense Trauma Registry reported in-hospital mortality based on whether patients received ketamine (dosage not reported) for acute pain management in the prehospital setting and found no difference in survival to hospital discharge between groups (75.1% ketamine vs 83% no ketamine) after controlling for the presence of an airway intervention and mechanism of injury (OR = 1.09, 95% CI [0.76, 1.55]). Most patients (95%) did not receive ketamine, and it is unclear what other pain medications (if any) those patients received.

Two RCTs^42,44^ comparing prehospital administration of ketamine to morphine or as an adjunct to fentanyl compared to placebo for acute pain management reported low rates (0–3%) of serious adverse events (a composite outcome commonly including cardiac arrest, invasive airway placement, or severe oxygen desaturation) with no differences based on receipt of ketamine. A single retrospective cohort^35^ comparing ketamine to fentanyl for severe acute pain in the prehospital setting found that adverse events (hemodynamic instability or respiratory compromise) occurred among only 4 of 200 participants, all of whom received fentanyl. Ketamine doses ranged from 0.1–0.2 mg/kg IV and 0.5–1.0 mg/kg IN.

In 4 RCTs, patients who received ketamine had a higher incidence of visual disturbance,^38,40^ emergence phenomena,^38,40^ and sedation^38–40,44^ (Table 2). Similarly, several RCTs comparing prehospital ketamine to placebo among patients already receiving another medication for acute pain (morphine, fentanyl, or nitrous oxide) found that patients who received ketamine had a higher incidence of dizziness^34,42^ and overall neuropsychological effects.^37,46^ No significant differences were reported in the occurrence of nausea and vomiting, hypertension, arrhythmia, respiratory problems, itching, fatigue, general discomfort, hearing changes, headache, hallucinations, or mood change in studies comparing rates of other adverse events between patients who received ketamine and those who received morphine or placebo. Findings for other adverse events including hypotension, feeling of unreality, and a composite outcome of any adverse event were inconsistent across studies.

One retrospective cohort^43^ examined the rates of PTSD diagnosis at 1 and 2 years among US combat casualties in Iraq or Afghanistan who received ketamine (with or without opioids) or opioids alone for acute pain management in the prehospital setting. At 1 year after injury, rates of PTSD were lower among those who received ketamine compared opioids alone (3% ketamine vs 24% opioids alone, OR = 0.08, 95% CI [0.01, 0.71]), but only among those who had not sustained TBI. Among participants who had sustained TBI, the study did not find any differences in PTSD diagnoses between groups at 2 years post-injury.

Several other adverse events, including advanced airway management or need for oxygen, aspiration, and agitation or anxiety, were each only reported in a single study, limiting our ability to assess differences in these outcomes with ketamine compared to other medications used for acute pain (see Supplementary Materials for full details). Likewise, among noncomparative and unadjusted studies (non-prioritized studies), adverse event reporting varied, and specific adverse events were often only reported in a single study (see Supplementary Materials for full study details).

Table 2 Summary of Adverse Events of Prehospital Ketamine for Acute Pain Management

Outcome | Comparator | Studies (Participants) | Summary of Findings | Consistency and Precision (Risk of Bias) | Strength of Evidence Summary
Any AE | Placebo | 2 RCTs^34,42^ (N range 120–199) | Increased occurrence of AEs with ketamine (62% KET vs 20% placebo, difference = 43%, 95% CI [24, 56]) in 1 study.; No difference in occurrence of AEs in 1 study. | Inconsistent and imprecise findings across studies. (Moderate) | INSUFFICIENT; It is unclear whether there is a difference in the occurrence of AEs overall with ketamine compared to placebo for acute pain management.
Any AE | Morphine | 3 RCTs^38,40,44^ (N range 135–449) | Increased occurrence of AEs with ketamine (40.8% KET vs 16.8% MOR, difference = 24%, 95% CI [12.8, 35.2] and 13.8% MOR vs 38.6% KET, difference −26%, 95% CI [−40.7, −10.6]) in 2 studies.; No difference in AEs in 1 study. | Inconsistent and imprecise findings across studies. (Low–Moderate) | INSUFFICIENT; It is unclear whether there is a difference in the occurrence of AEs overall with ketamine compared to placebo for acute pain management.
Cardiac: Arrhythmias | Morphine | 2 RCTs^38,44^ (N range 135–449) | No significant difference in tachycardia or arrhythmias between ketamine and morphine across studies. | Consistent but imprecise findings across studies. (Low–Moderate) | LOW; There may be little to no difference in arrythmias between ketamine and morphine for acute pain management.
Cardiac: Hypertension | Morphine | 3 RCTs^38,40,44^ (N range 135–449) | No significant difference in hypertension between ketamine and morphine across all studies. | Consistent and precise findings across studies (Low–Moderate) | MODERATE; There is likely little to no difference in hypertension between ketamine and morphine for acute pain management.
Cardiac: Hypotension | Morphine | 2 RCTs^38,44^ (N range 135–449) | Less hypotension with ketamine (3% KET vs 10% MOR, OR = 0.2, 95% CI [0.1, 0.6]) in 1 study.; No significant difference in hypotension in 1 study. | Precise but inconsistent findings across studies. (Low–Moderate) | LOW; It is unclear if there is a difference in the incidence of hypotension with ketamine compared to morphine for acute pain management.
GI: Nausea and/or Vomiting | Placebo | 4 RCTs^34,37,42,46^ (N range 66–199) | No significant difference in nausea/vomiting between ketamine and placebo in 3 studies.; More nausea with ketamine (17% ketamine vs 5% placebo, difference = 12%, 95% CI [0.3, 24]) in 1 study. | Inconsistent and imprecise findings across studies. (Moderate) | LOW; There may be little to no difference in nausea/vomiting between ketamine and placebo for acute pain management.
GI: Nausea and/or Vomiting | Morphine | 4 RCTs^38–40,44^ (N range 27–449) | No significant difference in nausea/vomiting between ketamine and morphine across all studies. | Consistent and precise findings across studies. (Low–High) | MODERATE; There is likely little to no difference in nausea/vomiting between ketamine and morphine for acute pain management.
M/B: Emergence phenomena | Morphine | 2 RCTs^38,40^ (N range 135–251) | Increased occurrence of emergence phenomena with ketamine (20% KET vs. 0.9% MOR, difference = 19.1%, 95% CI [11.7, 26.5]) in 1 study.; Nonsignificant increase in emergence phenomena in 1 study. | Consistent but imprecise findings across studies. (Low–Moderate) | LOW; There may be increased occurrence of emergence phenomena with ketamine compared to morphine for acute pain management.
M/B: Feeling of unreality | Placebo | 2 RCTs^34,42^ (N range 120–199) | Increased feeling of unreality (27% KET vs 2% placebo, difference = 25%, 95% CI [13, 37]) in 1 study.; No significant difference in feeling of unreality in 1 study. | Inconsistent and imprecise findings across studies. (Moderate) | LOW; It is unclear whether there is a difference in feeling of unreality between ketamine and placebo for acute pain management.
M/B: Hallucinations, Mood change | Placebo | 2 RCTs^34,42^ (N range 120–199) | No significant difference in hallucinations or mood change between ketamine and placebo in 2 studies. | Consistent but imprecise findings across studies. (Moderate) | LOW; There may be little to no difference in hallucinations or mood change between ketamine and placebo for acute pain management.
M/B: Neuropsychological effects | Placebo | 2 RCTs^37,46^ (N range 66–73) | Increased occurrence of neuropsychological effects with ketamine (36% KET vs 2% placebo, p = 0.0002); Nonsignificant increase in neuropsychological effects in 1 study. | Consistent but imprecise findings across studies. (Moderate) | LOW; There may be an increased occurrence of neuropsychological effects between ketamine and placebo for acute pain management.
M/B: Sedation | Morphine | 4 RCTs^38–40,44^ (N range 27–449) | Nonsignificant increase in sedation or decreased consciousness in 3 studies. No occurrence of sedation in 1 study. | Consistent but imprecise findings across studies. (Low–High) | LOW; There may be a slightly higher occurrence of sedation or decreased consciousness with ketamine compared to morphine for acute pain management.
Other: Dizziness | Placebo | 2 RCTs^34,42^ (N range 120–199) | Increased dizziness with ketamine (8% KET vs 1% placebo, difference = 7%, [1, 13]) in 1 study.; Nonsignificant increase in dizziness in 1 study. | Consistent but imprecise findings across studies. (Moderate) | LOW; There may be an increased occurrence of dizziness with ketamine compared to placebo for acute pain management.
Other: Fatigue, General discomfort, Hearing changes, Headache | Placebo | 2 RCTs^34,42^ (N range 120–199) | No significant difference in fatigue, general discomfort, hearing changes, or headache between ketamine and placebo across studies. | Consistent but imprecise findings across studies. (Moderate) | LOW; There may be little to no difference in fatigue, general discomfort, hearing changes, or headache between ketamine and placebo for acute pain management.
Other: Itching | Placebo | 2 RCTs^37,42^ (N range 73–199) | No difference in itching between ketamine and placebo across studies. | Consistent but imprecise findings across studies. (Moderate) | LOW; There may be little to no difference in itching between ketamine and placebo for acute pain management.
Other: Visual disturbance | Morphine | 2 RCTs^38,40^ (N range 135–251) | Increased visual disturbance with ketamine (17.5% KET vs 4.4% MOR, Difference = 13.1, 95% CI [5.3, 20.9]) in 1 study.; Nonsignificant increase in visual disturbance in 1 study. | Consistent but imprecise findings across studies. (Low–Moderate) | LOW; There may be an increase in visual disturbance with ketamine compared to morphine for acute pain management.
Respiratory problems | Placebo | 2 RCTs^37,42^ (N range 73–199) | No significant difference in bradypnea or breathing problems between ketamine and placebo across studies. | Consistent but imprecise findings across studies. (Moderate) | LOW; There may be little to no difference in respiratory problems between ketamine and placebo for acute pain management.

Notes. This table only includes outcomes with at least 2 studies examining the outcome with the same comparator.

Abbreviations. AE=adverse event; CI=confidence interval; GI=gastrointestinal; KET=ketamine; M/B=mental/behavioral; MOR=morphine; OR=odds ratio; RCT=randomized controlled trial.

### Benefits of Prehospital Ketamine for Acute Pain Management

Ketamine appears to be at least as effective as an opioid medication for acute pain management in the prehospital setting based on consistent findings across 6 studies (Table 3). Several studies reported that ketamine was associated with greater reductions in pain severity compared to fentanyl^35^ or another opioid,^36,38,39^ while other studies reported no significant difference. Likewise, several studies^35,40,42,46^ found that morphine requirements (an indirect measure of pain severity) were the same or lower among patients who received ketamine in the prehospital setting compared to other analgesics.

Among 4 studies comparing ketamine to placebo among patients also receiving another analgesic, ketamine was generally associated with improved pain outcomes, but findings were statistically significant in only 1 study.^34^ A single RCT examined utilization outcomes between patients receiving ketamine or morphine for acute pain management in the prehospital setting and found no difference in ED length of stay, hospital admission, or critical care admission.^44^

Table 3 Effectiveness Outcomes of Prehospital Ketamine for Acute Pain Management

Author, Year | Study Design | Comparator | Direction of Effect | Findings [95% CI]
Bronsky, 2019^35^ | Retrospective Cohort | Fentanyl | Ketamine beneficial | 50% pain reduction from baseline: 67% KET vs 19% FENT, p significant (value NR)
McArthur, 2025^41^ | Retrospective Cohort | Fentanyl | NSD | Effect size = −0.46 [−1.19, 0.28]
Cohen, 2022^36^ | Retrospective Cohort | Opioids alone | NSD | Mean pain change (VNRS): 4.3 KET vs 3.75 opioids, p = 0.095; effect size = 0.32 [−0.52, 1.16])
Jennings, 2024^38^ | RCT | Morphine alone | Ketamine beneficial | Mean pain change (VNRS): −5.6 KET vs −3.2 MOR; effect size = −2.4 [−3.2, −1.6]
Johansson, 2009^39^ | RCT | Morphine alone | Ketamine beneficial | Mean pain at hospital admission (NRS): 3.1 KET vs 5.4 MOR, p < 0.05
Le Cornec, 2024^40^ | RCT | Morphine | NSD | Mean pain change at 30 min. (VNRS): −3.6 KET vs −3.8 MOR; difference = 0.2 [0.5, 0.9]
Smyth, 2025^44^ | | Morphine | NSD | SPID score: 3.5 KET vs 3.4 MOR; mean difference = 0.1 [−0.4, 0.6]
Andolfatto, 2019^34^ | RCT | Placebo + Nitrous oxide | Ketamine beneficial | ≥ 2-point reduction at 30 min. (VNRS): 76% KET vs 41% placebo; difference = 35% [17, 51]
Galinski, 2007^37^ | RCT | Placebo + Morphine | NSD | Pain score (VAS) at 30 min.: 34.1 KET + MOR vs 39.5 placebo + MOR (p = NS)
McMullan, 2024^42^ | RCT | Placebo + Fentanyl | NSD | ≥ 2-point reduction at 30 min. (VNRS): 44.7% KET + FENT vs 36% placebo + FENT; difference = 8.7% [−5.1,22.5]
Wiel, 2015^46^ | RCT | Placebo + Morphine | NSD | VAS final pain score: 3.1 KET + MOR vs 3.7 placebo + MOR (p = NS)

Abbreviations. CI=confidence interval; FENT=fentanyl; KET=ketamine; min.=minutes; kg=kilogram; IM=intramuscular; IN=intranasal; IO=intraosseous; IV=intravenous; mg=milligram; MOR=morphine; NRS=numeric rating scale; NS=nonsignificant; NSD=no significant difference; SPID=sum of pain intensity differences; VAS=visual analog scale; VNRS=verbal numeric rating scale.

## SEDATION

### Safety of Prehospital Ketamine for Sedation

A single retrospective cohort^2^ by Muldowney et al reported mortality outcomes based on receipt of ketamine (5 mg/kg IM) or midazolam for sedation in the prehospital setting. In this study, which was conducted in the US among 376 patients experiencing acute behavioral disturbance in an urban EMS system, out-of-hospital, ED, and in-hospital mortality rates were low (0–2%) and did not differ between groups (ED deaths: 1% midazolam vs 0% ketamine, difference = 0.7%, 95% CI [-0.7, 2.1]; in-hospital deaths: 2% midazolam vs 1% ketamine, difference = 1.2%, 95% CI [-1.6, 4.0]; out-of-hospital deaths: 0% midazolam vs 0% ketamine).

Muldowney et al^2^ and another larger retrospective cohort by Brown et al^14^ comparing sedation with ketamine compared to benzodiazepines or antipsychotics in the prehospital setting found no significant differences in rates of cardiac arrest between groups, which were overall low (0.1% to 2%) (Table 4). The larger of these 2 studies, Brown et al^14^ (N = 7,973), used propensity score matching to minimize baseline differences among groups and found that the risk of post-sedation cardiac arrest was small (0.1% to 0.2%) and similar among those who received ketamine (dosage NR), a benzodiazepine, or an antipsychotic as initial treatment. However, the incidence of invasive airway placement, which was the most frequent serious adverse event reported in this study, was higher with receipt of ketamine as initial treatment compared to benzodiazepines (2% ketamine vs 0.6% benzodiazepines, difference = 1.4%, 95% CI [0.7, 2.1]) and compared to antipsychotics (1.5% ketamine vs 0.3% antipsychotics, difference = 1.2%, 95% CI [0.4, 2.0]). This study also found a higher incidence of serious adverse events overall (specifically due to a higher incidence of post-sedation invasive airway placement and new-onset severe oxygen desaturation) with ketamine compared to benzodiazepines (4% ketamine vs 1.6% benzodiazepines, difference = 2.4%, 95% CI [1.3, 3.4]) and compared to antipsychotics (3.1% ketamine vs 1.1% antipsychotics, difference = 2.1%, 95% CI [0.8, 3.3]).

Muldowney et al^2^ and another smaller retrospective cohort^1^ did not find a significant difference in the need for invasive airway placement when ketamine (dose = 5 mg/kg IM) was used for sedation. In Muldowney et al, the odds of receiving advanced airway management were similar with midazolam and ketamine (adjusted OR = 1.02, 95% CI [0.44, 2.38]) and no differences were observed in emergency department intubation rates (14% midazolam vs 11% for ketamine). The second study^1^ did not find a significant difference in the need for invasive airway placement when ketamine was conducted in the US among 135 patients treated by an EMS service that had implemented standing orders for ketamine in cases of “profound agitation,” defined as displays of active physical violence directed towards self or others when usual chemical or physical restraints may not be appropriate or safely used.^44^ In this study, in which all patients were subsequently transported to an urban level 1 trauma center, receipt of ketamine at doses ≤ 5mg/kg was not associated with need for intubation when adjusted for age, sex, ED arrival time (a surrogate measure for staffing and available resources), and co-administration of midazolam or haloperidol. In a retrospective cohort conducted in Italy that included 319 patients with psychomotor agitation, ketamine was significantly associated with a fraction of inspired oxygen (FiO2) requirement > 0.4 through a Venturi face mask.^47^ No patients in this study required intubation.

Two retrospective cohorts compared different dosages of ketamine in patients requiring sedation in the prehospital setting. One cohort^49^ of 2,383 patients receiving ketamine for behavioral concerns compared a high dose (> 2 mg/kg IV/IO or > 5 mg/kg IM) to a standard dose (≤ 2 mg/kg IV/IO or ≤ 5 mg/kg IM). A higher incidence of intubation was reported among patients receiving higher dose ketamine (6.4% high dose vs 3.3% standard dose, OR = 2.0, 95% CI [1.0, 3.9]). No significant differences were found for other respiratory outcomes including hypoxia or need for supplemental oxygen, or for cardiac outcomes including hypotension or cardiac arrest. A smaller retrospective cohort48 of 292 agitated patients compared adverse events after a change in EMS protocol directed paramedics to give an initial lower dose of ketamine (3 mg/kg IM) followed by an additional dose (1 mg/kg IM) if adequate sedation was not achieved. This dosage was compared to the previously directed standard dose (4 mg/kg IM). No significant differences in intubation or a composite outcome of any adverse events were reported, but there were significantly more assaults or injuries to EMTs and ED staff after implementing the lower dose ketamine protocol (43.2% low dose vs 19.4% standard dose). However, most of the staff assaults occurred prior to ketamine administration and therefore the observed increase may not have been related to the change in ketamine dosing.

The most frequently reported adverse events in noncomparative and unadjusted studies included intubation, laryngospasm, and respiratory depression (see Supplementary Materials for full study details). In a single noncomparative study^54^ of 68 patients treated with ketamine for severe agitation at a dance festival, 2 patients developed hypersalivation, 1 had transient apnea requiring approximately 2 minutes of assisted ventilation, and 1 was intubated due to persistent severe agitation.

Table 4 Summary of Adverse Events of Prehospital Ketamine for Sedation

Outcome | Comparator | Studies (Participants) | Summary of Findings | Consistency and Precision (Risk of Bias) | Strength of Evidence Summary
Cardiac arrest | Benzodiazepines | 2 Retrospective cohorts^2,14^ (N range 376–7973) | No significant difference in cardiac arrest between ketamine and benzodiazepines for sedation. | Consistent and precise findings across studies. (Moderate–Serious) | LOW; There may be no difference in the occurrence of cardiac arrest between ketamine and benzodiazepines for sedation.
Respiratory: advanced airway placement or need for oxygen | Benzodiazepines | 4 Retrospective cohorts^1,2,14,47^ (N range 135–7973) | Increase in invasive airway placement (2% KET vs 0.6% BENZ, difference = 1.4, 95% CI [0.7, 2.1]) and oral/nasal airway placement (6.3% KET vs 1.9% BENZ, difference = 4.4, 95% CI [3.2, 5.7]) with ketamine in the largest study.; Increase in need for oxygen with ketamine in 1 study.; No significant difference in intubation or advanced airway management in 2 studies. | Inconsistent but precise results across studies. (Moderate–Serious) | LOW; There may be an increase in advanced airway management or need for oxygen with ketamine compared to benzodiazepines for sedation.

Notes. This table only includes outcomes with at least 2 studies examining the outcome with the same comparator.

Abbreviations. BENZ=benzodiazepines; CI=confidence interval; KET=ketamine.

### Benefits of Prehospital Ketamine for Sedation

Brown et al,^14^ the large retrospective cohort described above, found less need for additional sedation when ketamine was used as initial treatment compared to benzodiazepines or antipsychotics (Table 5). However, Muldowney et al,^2^ a smaller retrospective cohort also discussed above, found no difference in the need for additional sedation with ketamine compared to benzodiazepines. Two cohorts evaluating different doses of ketamine administered in the prehospital setting did not find a difference in the need for additional sedation or restraints based on dose.^48,49^

Muldowney et al^2^ and another retrospective cohort^48^ reported no significant differences in hospital admission or length of stay when ketamine was administered in the prehospital setting compared to benzodiazepines or when lower doses of ketamine were compared to standard doses. One retrospective cohort^47^ reported shorter hospital length of stay for patients who received ketamine for acute agitation in the prehospital setting compared to benzodiazepines (2.48 days ketamine vs 2.66 days benzodiazepines, p = 0.03), but this difference may not be clinically significant.

Table 5 Effectiveness Outcomes of Prehospital Ketamine for Sedation

Author, Year | Study Design | Comparator | Direction of Effect | Findings [95% CI]
Brown, 2022^14^ | Retrospective cohort | Benzodiazepines Antipsychotics | Ketamine beneficial | Need for additional sedation: 28% KET vs 39.7% BENZ, difference = −11.7%, [−14.7, −8.7]; 25.7% KET vs 46.3% ANTIP, difference= −20.5%, [−24.6, −16.5]
Muldowney, 2024^2^ | Retrospective cohort | Benzodiazepines | NSD | No need for additional sedatives: 41% BENZ vs 41% KET, difference = 0.2%, [−10.4, 10.8]
Cunningham, 2021^48^ | Retrospective cohort | Low dose (3mg/kg) vs standard dose (4 mg/kg) IM KET | NSD | Need for additional restraint (any): 72.8% low dose vs 72% standard; OR = 1.04, [0.59, 1.85]; Need for additional restraint (chemical): 56.8% low dose vs 57.3% standard; OR = 0.98, [0.58, 1.64]
Sergot, 2024^49^ | Retrospective cohort | High dose (> 2 mg/kg IV/IO or > 5 mg/kg IM) vs standard dose (≤ 2 mg/kg IV/IO or ≤ 5 mg/kg IM) KET | NSD | Need for antipsychotics: 0.4% low dose vs 1.9% high dose; OR = 4.6, [0.98, 21.3]

Abbreviations. ANTIP=antipsychotics; BENZ=benzodiazepines; CI=confidence interval; IM=intramuscular; IO=intraosseous; IV=intravenous; KET=ketamine; kg=kilogram; mg=milligram; OR=odds ratio.

## RAPID SEQUENCE INTUBATION

### Safety of Prehospital Ketamine for Rapid Sequence Intubation

We did not identify any studies that evaluated mortality when ketamine was used in the prehospital setting for RSI compared to other medications.

Two cohorts^68,70^ comparing ketamine (1–2 mg/kg IV) to etomidate for patients undergoing RSI in the prehospital setting reported mixed results on the incidence of hypotension (Table 6). A retrospective cohort^68^ of 306 patients intubated by air medical services reported a lower incidence of hypotension (defined as systolic blood pressure [SBP] < 90 mmHG or a ≥ 5 mmHG decrease in SBP for those already hypotensive) with ketamine compared to etomidate as the induction agent (4.2% ketamine vs 9.6% etomidate, p = 0.028). However, another retrospective cohort^70^ of 116 patients intubated by EMS or air medical services reported no significant difference in hypotension (defined as a 20% or greater decrease in SBP from baseline) with ketamine compared to etomidate (18% ketamine vs 16% etomidate, p = 0.79). Most patients received etomidate (70%–84%) in these studies and rocuronium and succinylcholine were co-administered along with ketamine or etomidate. Inconsistent findings may be due to differences in the definition of hypotension and/or lack of full adjustment for baseline differences between groups in 1 of the studies.^70^

Two cohorts^69,71^ compared different doses of ketamine in patients undergoing RSI. In 1 of these studies, a retrospective cohort^71^ of 130 patients undergoing RSI that compared standard dose (≤ 2 mg/kg IV) to high dose (> 2 mg/kg IV) ketamine, patients receiving high dose ketamine had higher rates of hypotension, bradycardia, oxygen desaturation, laryngospasm, and agitation. No significant differences were reported between groups in the incidence of vomiting, hypertension, cardiac arrest, or tachycardia. Another retrospective cohort^69^ of 212 patients undergoing RSI compared half dose ketamine (1 mg/kg IV/IO) to standard dose ketamine (2 mg/kg IV/IO) and reported no differences in peri-intubation cardiac arrest based on dose. However, this study did not report baseline patient characteristics by intervention group or control for baseline group differences. These critical methodological limitations lower the usefulness of these findings.

Table 6 Summary of Adverse Events of Prehospital Ketamine for RSI

Outcome | Comparator | Studies (Participants) | Summary of Findings | Consistency and Precision (Risk of Bias) | Strength of Evidence Summary
Hypotension | Etomidate | 2 Retrospective cohorts^68,70^ (N range 113–306) | Less hypotension with ketamine (4.2% KET vs 9.6% ETO, p = 0.028) in 1 study.; No significant difference in hypotension between ketamine and etomidate in 1 study. | Inconsistent and imprecise findings across studies. (Moderate–Serious) | INSUFFICIENT; It is unclear if there is any difference in hypotension between ketamine and etomidate for RSI.

Notes. This table only includes outcomes with at least 2 studies examining the outcome with the same comparator.

Abbreviations. ETO=etomidate; KET=ketamine; RSI=rapid sequence intubation.

### Benefits of Prehospital Ketamine for RSI

Among studies utilizing ketamine for prehospital RSI, only 2 studies^70,71^ reported on intubation success (Table 7). Compared to high dose ketamine (> 2 mg/kg IV), standard dose ketamine (≤ 2 mg/kg IV) resulted in fewer instances of multiple intubation attempts and unsuccessful intubation. No significant differences were reported in first pass intubation success between ketamine and etomidate, with high rates of success in both groups (96%–97%).^70^

Table 7 Effectiveness and Utilization Outcomes of Prehospital Ketamine for RSI

Author, Year | Study Design | Comparator | Direction of Effect | Findings [95% CI]
Krebs, 2021^71^ | Retrospective cohort | Standard dose (≤ 2 mg/kg) vs high dose (> 2mg/kg) IV ketamine | Standard dose beneficial | Multiple intubation attempts: 23.8% standard dose vs 50% high dose; OR = 3.2 [1.5, 6.8]; Unsuccessful intubation: 5% standard dose vs 16% high dose; OR = 3.6 [1.0, 12.7]
Stanke, 2021^70^ | Retrospective cohort | Etomidate | NSD | First pass intubation success: 97% KET vs 96% ETO (p = 0.85)

Abbreviations. CI=confidence interval; ETO=etomidate; IV=intravenous; KET=ketamine; kg=kilogram; mg=milligram; NSD=no significant difference; OR=odds ratio.

## ANY INDICATION

Several studies did not specify the indication for prehospital ketamine use. A retrospective cohort^72^ using data from a previously conducted RCT examining the use of tranexamic acid for patients with moderate to severe TBI reported no differences in death within 6 months of injury, cardiac events, arrhythmia, hypotension, hypertension, or hypoxia between those with and without ketamine exposure in the prehospital setting. However, patients with exposure to ketamine had a significantly higher incidence of seizure activity (3.1% ketamine vs 1% no ketamine, p = 0.01), but significantly lower incidence of intracranial pressure elevation (56.3% ketamine vs 82.3% no ketamine, p = 0.048). Most participants in the study (84%) did not receive ketamine in the prehospital setting.

Additionally, a retrospective cohort^73^ of combat casualties from the Department of Defense Trauma Registry examined interventions associated with survival after prehospital intubation for any indication and reported that more patients who survived at least 7 days after injury received prehospital ketamine compared to those who did not survive at least 7 days after injury (29% survivors vs 17% non-survivors), but this difference was not significant in adjusted models of survivorship (OR =1 .43, 95% CI [0.96, 2.11]) and this study was not specifically designed to compare ketamine to other interventions. A noncomparative cohort^74^ of trauma patients receiving air medical services in the UK reported no deaths on the scene after administration of ketamine for any indication.