# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD420251029615 (https://www.crd.york.ac.uk/PROSPERO/view/CRD420251029615)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are provided in the Supplementary Materials.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

- Key Question 1 (KQ1): What are the harms of ketamine use for pain control, sedation, or rapid sequence intubation in the prehospital setting?
  ○ Key Question 1a (KQ1a): What are the benefits of ketamine use for pain control, sedation, or rapid sequence intubation in the prehospital setting?

Study eligibility criteria are shown in the table below. Given our interest in identifying all potential safety concerns related to ketamine use among adults in the prehospital setting, we included all relevant studies for KQ1 regardless of study design and included studies with a mix of adult and older adolescent participants (rather than restricting inclusion criteria to studies of adults only).

Domain | Eligibility Criteria
Population | Adult patients receiving prehospital emergency care^a^
Intervention | Ketamine^b^ (any administration method) for acute pain management, sedation, or RSI
Comparator | Any other intervention for acute pain management, sedation, or RSI or no comparator^c^
Outcomes | Harms (eg, mortality, nausea, vomiting, respiratory changes), benefits (eg, pain relief, sedation)
Study Design | Any, but may prioritize studies to fit timeline based on a best-evidence approach

Notes.

a We also included studies of adults and older adolescents (aged 15 or older) if they otherwise met eligibility criteria

b We excluded studies of IV esketamine, the S(+) enantiomer of ketamine, due to its different pharmacologic properties compared to ketamine

c For KQ1a, we excluded studies without a comparison group.

## SEARCHING AND SCREENING

To identify articles relevant to the key questions, a research librarian searched Ovid Medline, CDSR and CENTRAL via Cochrane Library, CINAHL Ultimate, and Scopus from inception through April 8, 2025, using terms for ketamine and prehospital or emergency medical services (see Appendix for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts. English-language titles, abstracts, and full-text articles were independently screened by 2 reviewers, and disagreements were resolved by consensus.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Effect information, adverse event incidence, and population, intervention, and comparator characteristics were abstracted from all included studies. Data were first abstracted by 1 reviewer and then checked by another. For randomized controlled trials (RCTs) and controlled observational studies that adjusted for baseline differences between groups (ie, controlled for potential confounding), 2 reviewers with systematic review methodology expertise independently evaluated internal validity (risk of bias) using the Cochrane Risk of Bias tools for randomized and nonrandomized studies.^26,27^ Disagreements were resolved by consensus or discussion with a third reviewer with clinical and systematic review methodology expertise (see the Supplementary Materials for risk of bias ratings). We did not evaluate internal validity for non-comparative (single group) studies or comparative studies that did not adjust for baseline differences between groups, given that these study designs are inherently less rigorous with a higher risk of bias.

## SYNTHESIS

We synthesized findings from included studies by ketamine indication and outcome. We prioritized synthesizing findings from RCTs and controlled observational studies that adjusted for baseline differences between groups, as these studies used methodologies best suited to isolate the effects of ketamine administered in the prehospital setting relative to other interventions. Mortality outcomes (if available) are presented first, followed by serious adverse event outcomes and then non-serious adverse event outcomes. Because the focus of this review is on ketamine’s safety, we present findings regarding effectiveness after discussing harms.

### Strength of Evidence

For adverse event outcomes reported in at least 2 studies with the same comparator, we rated the strength of evidence using criteria that considers study methodological limitations, the consistency and certainty of findings, and the directness of outcomes (whether reported outcomes are relevant to patients and providers).^28^ We used the following general algorithm: high strength evidence consisted of studies with consistent and precise findings at low risk of bias; moderate strength evidence consisted of studies with consistent and precise findings at low to moderate risk of bias; low strength evidence consisted of studies with moderate to high risk of bias and/or inconsistent or imprecise findings; and insufficient evidence consisted of studies with moderate or high risk of bias, indirect, inconsistent, and/or imprecise findings.