# BACKGROUND

Ketamine is a dissociative anesthetic that primarily acts as an N-methyl-D-aspartate (NMDA) receptor antagonist. It is FDA approved for procedural sedation and induction of general anesthesia and is used frequently in the hospital setting. Ketamine also has several pharmacologic properties that make it well suited for off-label use in the prehospital setting by emergency medical services (EMS) personnel, who are usually the first to treat patients with urgent or emergent medical needs. Prehospital care, defined as clinical care delivered by EMS prior to arrival at an emergency department (ED) or hospital, reduces patient morbidity and mortality and is an essential component of emergency medicine.^3^ In addition to causing neuro-inhibition and anesthesia through antagonism of NDMA receptors, ketamine is active at opioid receptors and provides rapid onset analgesia at low doses. It also has effects at catecholamine receptors, which make it a favorable agent to use for rapid sequence intubation (RSI) among hemodynamically unstable patients as it leads to increases in heart rate, contractility, and mean arterial pressure.^4,5^ Ketamine may be administered by intravenous (IV), intramuscular (IM), intraosseous (IO), or intranasal (IN) routes, adding to its usefulness in a range of clinical scenarios.

Guidelines and position statements from multiple professional societies support the use of ketamine for in-hospital analgesia and procedural sedation, prehospital pain management, RSI, and/or treatment of acute behavioral agitation.^6–10^ Additionally, national EMS clinical guidelines include recommendations for the use of ketamine for pain management and treatment of behavioral agitation.^11^ Ketamine has been broadly integrated into national and state EMS protocols and is now widely used as an agent for acute pain, sedation, and RSI in the prehospital setting. Within VHA, ketamine is an option for acute pain treatment and management of patients with acute behavioral agitation in the ED.^12,13^

Although ketamine is generally recognized as an effective treatment that is safe to use in the prehospital setting, its versatility as a pharmacologic agent has also led to concerns regarding its overuse or inappropriate use as a “catch-all” treatment, potentially placing some patients at unnecessary risk of harms. These concerns intensified following media reports of cardiac arrest and other adverse events occurring among people who received ketamine in the prehospital setting. After a man in Colorado died following ketamine administration by EMS personnel, the state passed a law in 2021 outlining criteria for ketamine use in the prehospital setting, including having the ability to weigh patients to determine appropriate dosing.^14,15^ Potential adverse effects of ketamine include nausea and vomiting, hypotension, laryngospasm, and respiratory depression.^16,17^ At higher doses, ketamine may also lead to “emergence phenomena,” which is characterized by euphoria, illusions, delirium, and/or hallucinations that can cause agitation and combativeness as ketamine is wearing off.^18,19^ Estimates of the incidence of emergence phenomena vary, but studies have reported such reactions in up to 55% of patients treated with ketamine.^18^ Lastly, some concern exists regarding the risk of elevated intracranial pressure with ketamine use among patients with head injury,^5^ although large studies in this area have shown conflicting results,^19^ and a Cochrane systematic review^20^ reported no increase in intracranial pressure with ketamine among sedated and ventilated patients with severe traumatic brain injury (TBI).

Several existing systematic reviews^21–25^ have examined the use of ketamine in the prehospital setting for acute pain, agitation, and RSI, and have generally found that ketamine is safe and effective when used appropriately. However, these reviews have largely included studies conducted in the ED and extrapolated findings to the prehospital setting. More evidence specific to the prehospital setting has become available as EMS providers seek to improve guidance for the field and ensure the safety of EMS treatment protocols. The VA Evidence Synthesis Program Coordinating Center (ESP CC) is responding to a request from the VA National Emergency Medicine Office (NEMO) for a review of evidence on the safety of ketamine for acute pain management, sedation, and RSI in the prehospital setting. Findings will be used to inform national protocols for VHA paramedics and EMTs.