# Appendices

## SEARCH STRATEGIES

### MEDLINE

Ovid MEDLINE Epub Ahead of Print and In-Process, In-Data-Review & Other Non-Indexed Citations and Daily April 07, 2025

# | Search Statement | Results
1 | Ketamine/ or (arketamine or calipsol or calypsol or kalipsol or ketajet or ketalar or ketamine or ketanest or ketastet or CI-581 or CI582 or esketamine or kataved or spravato).ti,ab,kf | 27256
2 | exp Ambulances/ or Emergency Medical Services/ or Emergency Medical Technicians/ or Emergency Medicine/ or exp Emergency Responders/ or Emergency Treatment/ or Evidence-Based Emergency Medicine/ or First Aid/ or Paramedicine/ or Triage/ or (ambulance* or (emergency adj3 (care or evacuation or helicopter* or medicine or personnel or practitioner* or rescue* or respon* or resus* or service* or technician* or treat* or therap* or triag* or unit*)) or ems or emt or fire fighter* or firefighter* or (first adj1 (aid or responder*)) or medevac or medivac or paramedic* or out-of-hospital or pre-hospital or prehospital or (rescue adj3 (personnel or service*))).ti,ab,kf | 267237
3 | Military Medicine/ or (battlefield or combat or (field adj3 (medical or technician*)) or medic or medics or military medicine).ti,ab,kf | 102583
4 | 2 or 3 | 365470
5 | 1 and 4 | 757
6 | limit 5 to dt=20190509-20251231 | 303
| Total | 303

Search date: 04/08/2025

### COCHRANE LIBRARY

# | Search Statement | Results
1 | MeSH descriptor: [Ketamine] this term only | 3203
2 | (arketamine or calipsol or calypsol or kalipsol or ketajet or ketalar or ketamine or ketanest or ketastet or CI-581 or CI582 or esketamine or kataved or spravato):ti,ab,kw | 9020
3 | #1 or #2 | 9020
4 | MeSH descriptor: [Ambulances] explode all trees | 252
5 | MeSH descriptor: [Emergency Medical Services] this term only | 1497
6 | MeSH descriptor: [Emergency Medical Technicians] this term only | 225
7 | MeSH descriptor: [Emergency Medicine] this term only | 366
8 | MeSH descriptor: [Emergency Responders] explode all trees | 521
9 | MeSH descriptor: [Emergency Treatment] this term only | 372
10 | MeSH descriptor: [Evidence-Based Emergency Medicine] this term only | 6
11 | MeSH descriptor: [First Aid] this term only | 130
12 | MeSH descriptor: [Paramedicine] this term only | 3
13 | MeSH descriptor: [Triage] this term only | 0
14 | (ambulance* or (emergency NEAR/3 (care or evacuation or helicopter* or medicine or personnel or practitioner* or rescue* or respon* or resus* or service* or technician* or treat* or therap* or triag* or unit*)) or ems or emt or fire fighter* or firefighter* or (first NEAR/1 (aid or responder*)) or medevac or medivac or paramedic* or out-of-hospital or pre-hospital or prehospital or (rescue NEAR/3 (personnel or service*))):ti,ab,kw | 21961
15 | {or #4-#14} | 22088
16 | MeSH descriptor: [Military Medicine] this term only | 204
17 | (battlefield or combat or (field NEAR/3 (medical or technician*)) or medic or medics or military medicine):ti,ab,kw | 3761
18 | #16 or #17 | 3761
19 | #15 or #18 | 25595
20 | #3 and #19 | 293
21 | limit 20 to 2019–2025 | 127
| Total | 127

Search date:04/08/2025

### CINAHL ULTIMATE

# | Search Statement | Results
1 | (MH “Ketamine”) OR TX ((arketamine or calipsol or calypsol or kalipsol or ketajet or ketalar or ketamine or ketanest or ketastet or CI-581 or CI582 or esketamine or kataved or spravato)) OR AB ((arketamine or calipsol or calypsol or kalipsol or ketajet or ketalar or ketamine or ketanest or ketastet or CI-581 or CI582 or esketamine or kataved or spravato)) | 6526
2 | (MH “Ambulances”) or (MH “Aeromedical Transport”) or (MH “Emergency Medical Services”) or (MH “Emergency Medical Technicians”) or (MH “Emergency Medicine”) or (MH “Emergency Responders+”) or (MH “Emergency Treatment”) or (MH “First Aid”) or (MH “Paramedicine”) or (MH “Triage”)) OR TI ((ambulance* or (emergency N3 (care or evacuation or helicopter* or medicine or personnel or practitioner* or rescue* or respon* or resus* or service* or technician* or treat* or therap* or triag* or unit*)) or ems or emt or fire fighter* or firefighter* or (first N1 (aid or responder*)) or medevac or medivac or paramedic* or out-of-hospital or pre-hospital or prehospital or (rescue N3 (personnel or service*)))) AND AB ((ambulance* or (emergency N3 (care or evacuation or helicopter* or medicine or personnel or practitioner* or rescue* or respon* or resus* or service* or technician* or treat* or therap* or triag* or unit*)) or ems or emt or fire fighter* or firefighter* or (first N1 (aid or responder*)) or medevac or medivac or paramedic* or out-of-hospital or pre-hospital or prehospital or (rescue N3 (personnel or service*)))) | 89089
3 | (MH “Military Medicine”) OR TI ((battlefield or combat or (field N3 (medical or technician*)) or medic or medics or military medicine)) OR AB ((battlefield or combat or (field N3 (medical or technician*)) or medic or medics or military medicine)) | 22833
4 | S2 or S3 | 110566
5 | S1 and S4 | 311
6 | (S1 and S4) and EM 20190509-20251231 | 115
| Total | 115

Search date: 04/08/2025

### SCOPUS

# | Search Statement | Results
1 | TITLE-ABS-KEY ((arketamine OR calipsol OR calypsol OR kalipsol OR ketajet OR ketalar OR ketamine OR ketanest OR ketastet OR ci-581 OR ci582 OR esketamine OR kataved OR spravato)) | 71622
2 | TITLE-ABS-KEY (ambulance* OR (emergency W/3 (care OR evacuation OR helicopter* OR medicine OR personnel OR practitioner* OR rescue* OR respon* OR resus* OR service* OR technician* OR treat* OR therap* OR triag* OR unit*)) OR ems OR emt OR fire-fighter* OR firefighter* OR (first W/1 (aid OR responder*)) OR medevac OR medivac OR paramedic* OR out-of-hospital OR pre-hospital OR prehospital OR (rescue W/3 (personnel OR service*))) | 54636
3 | TITLE-ABS-KEY ((battlefield OR combat OR (field W/3 (medical OR technician*)) OR medic OR medics OR “military medicine”)) | 254883
4 | 2 or 3 | 794254
5 | 1 and 4 | 2785
6 | 5 and ORIG-LOAD-DATE AFT 20190509 | 1180
| Total | 1180

Search date: 04/08/2025

Database | | Results
Ovid Medline | | 303
CDSR and CENTRAL (Cochrane Library) | | 127
CINAHL Ultimate (EBSCO) | | 115
Scopus (Elsevier) | | 1180
| Total | 1725
| Total after deduplication | 1354