# ABBREVIATIONS TABLE

Abbreviation: Definition
AE: Adverse event
AIS: Abbreviated Injury Scale
APVU: Alert, Verbal, Pain, Unresponsive Scale
BAN: Breath actuated nebulizer
CI: Confidence interval
ED: Emergency department
EMS: Emergency medical services
EMT: Emergency medicine technician
FDA: Food and Drug Administration
ICU: Intensive care unit
IM: Intramuscular
IN: Intranasal
IO: Intraosseous
ISS: Injury severity score
IV: Intravenous
LOS: Length of stay
MME: Morphine equivalent dose
NEMO: National Emergency Medicine Office
NRS: Numerical rating scale
NSD: No significant difference
OR: Odds ratio
PTSD: Posttraumatic stress disorder
RC: Retrospective cohort
RCT: Randomized controlled trial
RSI: Rapid sequence intubation
SPID: Sum of pain intensity
TBI: Traumatic brain injury
VAS: Visual analog scale
VNRS: Verbal numerical rating scale