# Supplementary Materials

- Comparative Adj. Study Details (XLSX)
- Comparative_Adj. Outcomes (XLSX)
- Noncomp_UnAdj. Study Details (XLSX)
- Noncomp._UnAdj. Outcomes (XLSX)
- Noncomp._UnAdj. Harms Summary (XLSX)
- Underway Studies (XLSX)
- Excluded Studies (XLSX)
- Risk of Bias Assessments - RCT (XLSX)
- Risk of Bias Assessments - NRCT (XLSX)
- Peer Review Feedback (XLSX)

## VA Related Documents

Supplementary Materials (XLSX)