# REFERENCES

1 Rubenstein LV. Integrating behavioral health and primary care. Integrating physical and mental health care in the Veterans Health Administration: A path to the future. Oxford University Press; 2017:90–106.
2 Chuah FLH, Haldane VE, Cervero-Liceras F, Interventions and approaches to integrating HIV and mental health services: a systematic review. Health policy and planning. 2017;32(suppl_4):iv27–iv47. doi:10.1093/heapol/czw169 29106512
3 Goldhammer H, Marc LG, Chavis NS, Interventions for Integrating Behavioral Health Services Into HIV Clinical Care: A Narrative Review. Open forum infectious diseases. 2022;9(8):ofac365. doi:10.1093/ofid/ofac365 35967264
4 Breland JY, Mignogna J, Kiefer L, Marsh L. Models for treating depression in specialty medical settings: a narrative review. General hospital psychiatry. 2015;37(4):315–22. doi:10.1016/j.genhosppsych.2015.04.010 25956666
5 SAMHSA-HRSA Center for Integrated Health Solutions. National Council for Mental Wellbeing. https://www.thenationalcouncil.org/resources/standard-framework-for-levels-of-integrated-care/
6 Sterne JAC, Savovic J, Page MJ, RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. Aug 28 2019;366:l4898. doi:10.1136/bmj.l4898 31462531
7 Sterne JA, Hernan MA, Reeves BC, ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. Oct 12 2016;355:i4919. doi:10.1136/bmj.i4919 27733354
8 English CMC. Screening Isnť Enough: A Call to Integrate Behavioral Health Providers in Women's Health and Perinatal Care Settings. International journal of integrated care. 2020;20(4):12. doi:10.5334/ijic.5640
9 Bekelman DB, Allen LA, McBryde CF, Effect of a Collaborative Care Intervention vs Usual Care on Health Status of Patients With Chronic Heart Failure: The CASA Randomized Clinical Trial. JAMA internal medicine. 2018;178(4):511–519. doi:10.1001/jamainternmed.2017.8667 29482218
10 Gillman A, Zhang D, Jarquin S, Karp JF, Jeong J- H, Wasan AD. Comparative Effectiveness of Embedded Mental Health Services in Pain Management Clinics vs Standard Care. Pain medicine (Malden, Mass). 2020;21(5):978–991. doi:10.1093/pm/pnz294 31994692
11 Irwin KE, Park ER, Fields LE, Bridge: Person-Centered Collaborative Care for Patients with Serious Mental Illness and Cancer. The oncologist. 2019;24(7):901–910. doi:10.1634/theoncologist.2018-0488 30696722
12 Carney RM, Freedland KE, Steinmeyer BC, Rubin EH, Ewald G. Collaborative care for depression symptoms in an outpatient cardiology setting: A randomized clinical trial. International journal of cardiology. 2016;219:164–71. doi:10.1016/j.ijcard.2016.06.045 27327502
13 Flicek CB, Sowa NA, Long MD, Herfarth HH, Dorn SD. Implementing Collaborative Care Management of Behavioral Health for Patients with Inflammatory Bowel Disease. Inflammatory intestinal diseases. 2022;7(2):97–103. doi:10.1159/000521285 35979188
14 Huffman JC, Mastromauro CA, Beach SR, Collaborative care for depression and anxiety disorders in patients with recent cardiac events: the Management of Sadness and Anxiety in Cardiology (MOSAIC) randomized clinical trial. JAMA internal medicine. 2014;174(6):927–35. Erratum in: JAMA Intern Med. 2014 Aug;174(8):1419Comment in: JAMA Intern Med. 2014 Jun;174(6):936–7 PMID: 24733142 [https://www.ncbi.nlm.nih.gov/pubmed/24733142]. doi:10.1001/jamainternmed.2014.739 24733277
15 Kanwal F, Pyne JM, Tavakoli-Tabasi S, Collaborative Care for Depression in Chronic Hepatitis C Clinics. Psychiatric services (Washington, DC). 2016;67(10):1076–1082.
16 Kanwal F, Pyne JM, Tavakoli-Tabasi S, A Randomized Trial of Off-Site Collaborative Care for Depression in Chronic Hepatitis C Virus. Health services research. 2018;53(4):2547–2566. doi:10.1111/1475-6773.12758 28891153
17 Painter JT, Fortney JC, Gifford AL, Cost-Effectiveness of Collaborative Care for Depression in HIV Clinics. Journal of acquired immune deficiency syndromes (1999). 2015;70(4):377–85. doi:10.1097/QAI.0000000000000732 26102447
18 Pyne JM, Fortney JC, Curran GM, Effectiveness of collaborative care for depression in human immunodeficiency virus clinics. Arch Intern Med. Jan 10 2011;171(1):23–31. doi:10.1001/archinternmed.2010.395 21220657
19 Walker J, Hansen CH, Martin P, Integrated collaborative care for major depression comorbid with a poor prognosis cancer (SMaRT Oncology-3): a multicentre randomised controlled trial in patients with lung cancer. Lancet Oncol. Sep 2014;15(10):1168–76. doi:10.1016/S1470-2045(14)70343-2 25175097
20 Walker J, Hobbs H, Wanat M, Implementing collaborative care for major depression in a cancer center: An observational study using mixed-methods. General hospital psychiatry. 2022;76:3–15. doi:10.1016/j.genhosppsych.2022.03.003 35305403
21 Davis JD, Bepo L, Suen LW, Implementing Heart Plus: Design and Early Results of a Novel Comanagement Clinic for Patients With Stimulant-associated Cardiomyopathy. Journal of cardiac failure. 2023;doi:10.1016/j.cardfail.2023.10.481
22 Sharpe M, Walker J, Holm Hansen C, Integrated collaborative care for comorbid major depression in patients with cancer (SMaRT Oncology-2): a multicentre randomised controlled effectiveness trial. Lancet (London, England). 2014;384(9948):1099–108. Comment in: Lancet. 2014 Sep 20;384(9948):1076–8 PMID: 25175951 [https://www.ncbi.nlm.nih.gov/pubmed/25175951] Comment in: Evid Based Ment Health. 2015 May;18(2):62 PMID: 25873536 [https://www.ncbi.nlm.nih.gov/pubmed/25873536]. doi:10.1016/S0140-6736(14)61231-9 25175478
23 Strong V, Waters R, Hibberd C, Management of depression for people with cancer (SMaRT oncology 1): a randomised trial. Lancet. Jul 5 2008;372(9632):40–8. doi:10.1016/S0140-6736(08)60991-5 18603157