# ACKNOWLEDGMENTS

The authors are grateful to Becky Nelson for literature searching, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Jennifer Patterson, PhD, ABPP
  National Director, Integrated Services
  VHA Office of Mental Health, VA Central Office

## Key Informants

The ESP sought input from key informants with diverse experiences and perspectives relevant to the review topic. Key informants included:

- Evelyn Chang, MD, MSHS
  Deputy Chief of Primary Care
  VA Greater Los Angeles Healthcare System
- Lucinda Leung, MD, MPH, PhD
  General Internal Medicine Physician and Health Services Researcher
  VA Greater Los Angeles Healthcare System
- Alexander Young, MD, MSHS
  Associate Director, Veterans Desert Pacific MIRECC Health Services Unit
  VA Greater Los Angeles Healthcare System