# DISCUSSION

The key findings from this review are that: 1) there are no published studies relevant to VA of full collaboration in a transformed/integrated practice for integrating mental health into specialty clinics; 2) there are only 3 published studies of close collaboration approaching an integrated practice or close collaboration onsite with some system integration (in other words, anything greater than basic collaboration); the study most relevant to VA was a multicomponent intervention that in addition to psychosocial care included a multidisciplinary team of heart failure clinicians who provided advice on laboratory tests and medications. One of 3 sites where the intervention was implemented was VA. There were no statistically significant effects of the intervention on disease-specific quality of life, but symptoms of depression and anxiety were better in the intervention patients compared to usual care; 3) there is a larger number of studies of basic collaboration, the studies most relevant to VA (done in VA settings) had interventions based on TIDES, modified for specific diseases (liver disease and HIV). Both studies were randomized trials and both found improvements in intervention patients compared to usual care on depression outcomes.

Limitations

The limitations of any systematic review can be put into 2 categories: limitations in the source material and limitations of the review process. Limitations in the source material include: relatively few studies, in fact none relevant to VA of full collaboration; methodologic limitations of the included studies (about half the included studies were observational in design, and some of these were missing key data like sample size and valid comparison groups); almost all studies were focused on depression, thus there is even less known about other mental health disorders. Lastly, there is always the possibility that relevant studies were never found because they were never published, because they did not achieve the results their proponents had hoped to find. This publication bias is difficult to disprove, and if present would tend to make the overall results more positive than they actually are.

Limitations of the review process always include the possibility that we did not identify all relevant studies. For example, we did not search for collaborative care by condition, as such a search would have been prohibitively large, and therefore might have missed studies that enrolled patients by condition rather than clinic but whose non-mental health care was delivered by a relevant outpatient specialty clinic. We did search the 2 databases most likely to contain studies of this type, namely Medline and PsycInfo, and furthermore our yield was reviewed by several experts, none of whom identified important missing studies that met our inclusion criteria. Also, we did not use 2 reviewers for screening titles, we used the DistillerSR AI function as the second title screener. There is a chance that this might have overlooked some relevant studies with low predicted probability of being included, but we did some validity checks on this plus, as above, several experts who reviewed the yield did not identify any important missing studies. We also did not use 2 reviewers for data extraction; although data were checked for accuracy, there is always the possibility of data extraction errors. Lastly, we could not assess the certainty of evidence for each outcome by intervention, because there were too few studies of specific intervention outcomes to justify such an assessment.

## FUTURE RESEARCH

Future research may wish to explore expanding out the successful TIDES model to other specialty clinics (only tested in HIV clinic and liver clinic to date); or the PCMHI model. Determining which specialty care clinics are most likely to benefit patients from mental health integration is also needed. There is a need for research and evaluation of the integration of co-located collaborative care into outpatient specialty medical programs, since this is part of the required integrated care approach in primary care. Lastly, specialty providers may need targeted educational training on appropriate co-management of mental health conditions.

## CONCLUSIONS

There is insufficient evidence from the published literature to guide how best to integrate mental health care into specialty care. In the VA setting, the intervention with the most evidence to support its beneficial effect is a specialty-clinic modification of TIDES.