# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

## OVERVIEW OF INCLUDED STUDIES

Our search identified 6,392 potentially relevant articles after deduplication and title and abstract screening. Of these, 14 primary studies (in 16 publications) met eligibility criteria. Characteristics of included studies are shown in Table 1. One study was level 6 integration (full collaboration in a transformed/merged integration practice),^8^ 1 study was level 5 integration (close collaboration approaching an integrated practice),^9^ 2 studies were level 4 integration (close collaboration onsite with some system integration),^10,11^ 7 studies (in 9 publications) were level 3 integration (basic collaboration onsite),12–20 and 3 studies were level 2 integration (basic collaboration at a distance).^19,21,22^ Eight studies were randomized trials^9,12,14–19,22,23^ and 6 studies used nonrandomized designs,^8,10,11,13,20,21^ of which 4 were case series/pre-post studies.^8,11,13,21^ Because these studies are impossible to blind, all randomized studies were judged to be at high risk of bias in at least 1 domain, while 3 of the 6 nonrandomized studies were judged to be at high risk of bias due to possible confounding.^8,13,20^ Nine of the studies were performed in single clinic or practice locations, and 5 studies (in 7 publications) were multisite. Three studies were performed in VA settings,^9,15–18^ 4 studies were performed in the United Kingdom,^19,20,22,23^ and the rest at single US sites.

### Approaches That Have Been Used and Outcomes of Integration of Mental or Behavioral Health Into Specialty Care

The narrative that follows refers to Table 2 and presents the results of studies that have sought to integrate mental or behavioral health into specialty outpatient care, according to how the authors described the integration and our assessment of the degree of integration (according to the CIHS Levels of Integration).^5^

#### Described as Embedded

Two studies were described by the authors as embedded. One study we judged to be level 4 integration, and embedded mental health services into a pain management clinic.^10^ This was a controlled before-and-after study of 453 patients who attended at least 3 appointments with a clinical psychologist in either an individual or group setting. Patients were attending the pain medicine clinic at a large academic urban teaching hospital and had been evaluated by a pain specialist physician. The comparison group consisted of 8,383 patients attending the same clinic who did not attend at least 3 clinical psychologist appointments. Propensity scoring on age, sex, race, body mass index, International Classification of Diseases (ICD)-10 diagnoses, insurance status, Charlson comorbidity index, tobacco, alcohol or illicit drug use, and categories of medications was used with an inverse probability weighting method to assess the effect of the mental health services. Intervention patients improved more than comparison patients in a few standardized outcomes at 3 or 6 months, namely a measure of the change for the most recent treatment and also the patient’s overall impression of change. Many other measures improved equally in both groups, such as average pain intensity, pain interference and pain behavior, and a few outcome measures improved more in the control group (global physical health, anxiety, and neuropathic pain).

We identified a second study described by the authors as embedded, which we judged to be level 6 integration.^8^ This involved the inclusion of a behavioral health provider into a women’s health and perinatal care clinic. The study reported that 91% of patients preferred behavioral health be integrated into women’s health care, and 73.9% thought that integrated behavioral health greatly improved the perinatal experience. The context of this study, and the methodologic limitations of it (no sample size reported, no pre-intervention data reported, no control group per se) make it of limited usefulness to VA.

#### Described as Based on TIDES

We identified 2 studies, in 4 publications, performed in VA settings: 1 study in liver clinics^15,16^ and the other study in HIV clinics.^17,18^ Both interventions were modeled after the successful TIDES intervention to improve depression outcomes in primary care.^1^ TIDES is a multimodal model for collaborative care between primary care and mental health for identification and treatment of depression. It includes interactions between the primary care clinician, a mental health specialist, and a care manager, all of whom interact with each other. The care manager supports the primary care clinician by interacting directly with the patient for periodic assessments, education, and time-limited follow-up (meaning 6 months after detection) and reviews their panel of patients with the mental health specialist weekly. The model includes decision support, patient self-management support, community resources, and clinical information systems to promote informed, active patients. Basic design features of TIDES include systematic screening for depression via an EHR clinical reminder, initial assessment, and proactive follow-up, with mental health supervision of the care manager, and can be completely carried out by telephone. There is a heavy emphasis on patient education and activation.

Both specialty care TIDES modifications involved an offsite depression care management team who interacted with the onsite specialist clinicians, this interaction happening solely by notes in the electronic health record. The depression care management team also communicated with the patient by telephone. Both interventions were judged to be level 3 integration. Like the parent TIDES intervention, both of these disease-specific modifications of TIDES found that intervention patients improved on a number of depression outcomes.

#### Described as Collaborative Care

We identified 4 studies described as collaborative care One of these was performed in part in a VA setting. ^9^ Three of the studies were judged to be level 3 integration^12–14^ and 1 study was judged to be level 5 integration.^9^ This 2-arm, multisite randomized clinical trial was conducted in 3 settings in Colorado: an academic medical center, a Veterans Affairs system, and a safety-net health system. The intervention was aimed at patients with heart failure and depression. Patients did not have to be enrolled in cardiology clinic to be eligible, but 75% of patients did see a cardiologist. The intervention had 3 components: assessment of symptoms by a nurse; a social worker who provided structured psychosocial care, and a multidisciplinary team (including a social worker) reviewing care and making suggestions for tests and medications. The 3 symptoms targeted were pain, breathlessness, and fatigue and depression. Usual care patients received care at the discretion of their clinicians. Enrolled patients were mostly male, with a mean age of about 65 years, and about one-third had depression. Among 158 patients randomized to the intervention, there were no statistically significant differences compared to 159 usual care patients in 6 month outcomes on a disease-specific measure of health-related quality of life, but depressive symptoms on the PHQ-9 modestly improved; 3 month (but not 6 month) outcomes anxiety on the General Anxiety Disorder (GAD)-7 also were somewhat better.

Two more studies assessed off-site collaborative depression care (similar to but not the same as in TIDES) for patients attending an urban academic teaching hospital cardiology clinic,^12^ and off-site depression and anxiety collaborative care for patients initially identified during an inpatient urban academic teaching hospital admission for an acute cardiac illness (arrythmia = 29%, heart failure = 22%, myocardial infarction = 24%, unstable angina = 26%) but then followed as outpatients by telephone every 6 weeks,^14^. The first of these RCTs did not find beneficial effects, but the second RCT reported statistically significant improvements in some measures of mental health and depression.

The fourth study was observational and used off-site collaborative care for patients with anxiety or depression and inflammatory bowel disease.^13^ This small study (N = 19) found that specialists agreed the collaborative care was “a highly beneficial resource” for providers and patients in the specialty clinic. Clinical outcomes were not statistically significantly different between pre- and post-measurements.

#### Variously Described as Collaborative Care, Then Integrated Care

We identified 4 studies, all related, for which the intervention was described as collaborative and later integrated care.^19,20,22,23^ All studies were set in the United Kingdom, 3 of them in regional cancer centers in Scotland and the fourth a mixed-methods study of implementation in the Oxford cancer center. Two of these studies were judged to be level 2 integration and the other 2 studies were judged to be level 3 integration. All studies involved integrating depression care into primary care and oncology clinic care. The first study, an RCT, used onsite and offsite depression care management delivered by a nurse to patients attending a regional cancer center in Scotland. It found sustained improvements in depression symptoms at 3, 6, and 12 months. Two follow-on studies were RCTs, one described as integrated collaborative depression care and the other as onsite and offsite depression care, and both also found improvements in a number of measures of mental health (depression, anxiety) but also physical symptoms such as fatigue and pain, as well as health-related quality of life. ^19,22^ The fourth study used mixed methods to assess the implementation at an Oxford University cancer center of offsite and onsite collaborative care for depression^20^ (related to the intervention used in Scotland, above) and found that specialists agreed the collaborative care was a good thing to have in the specialty clinic.

#### Comanagement Program

We identified 1 study described as a co-management program. It was a small (N = 22) case series with pre-post measures of adding an addiction care team to an academic urban safety net hospital clinic for stimulant-induced cardiomyopathy.^21^ This study’s design and small size make it of limited usefulness to VA.

#### Miscellaneous

We identified 1 study that we could not classify with any of the others. It assessed an intervention to assess and treat serious mental illness (schizophrenia, bipolar disorder, severe major depression) in an oncology clinic.^11^ The study was a small case series of 25 patients (of 33 eligible) who completed assessments at all time points. The study was conducted in a large academic teaching hospital. The intervention consisted or early tracking and identification of clinic patients with serious mental illness (SMI); person-centered assessment and care; multidisciplinary team-based care; and increased access to a psychiatrist. Enrolled patients completed a number of questionnaires up to 20 weeks. There was no control group per se. Clinician ratings of improvement, namely the clinical global impression-severity component and the Brief Psychiatric Rating Scale, and patient assessments of health (such as Patient Health Questionnaire [PHQ]-9) did not improve. This study’s small size and lack of a usual care control group limits its usefulness to VA.

Table 2 Characteristics of Included Studies

Name, Year, ID | Study Design, Sample Size | Setting | What’s the Intervention or What’s Being Integrated | What Is It Being Integrated Into | Level of Collaboration/Integration^a^ | Outcomes Assessed
Described as Embedded
Gillman, 2020^10^ | Controlled before and after Embedded MH; N = 451; Standard care; N= 8383 | One academic medical center (Pitt) | Embedded mental health services | Pain clinic | 4 | Mixed results on14 measures from PROMIS, with one some better in the MH group and others better in the standard care group.
English, 2020^8^ | Case series with pre/post measures; N = not stated | One community care clinic | Doctor of Behavioral Health | Midwife center for birth and wellness | 6 | 74% of women said having integrated behavioral health greatly improved the perinatal experience.
Based on TIDES
Kanwal, 2016^15^; Kanwal, 2018^16^ | RCT; N = 242 | Four VA liver clinics | Offsite collaborative depression care | Liver clinic | 3 | Remission of depression at 12 months: 19.3% in intervention group, vs 7% in standard care group (p = 0.004); starting antiviral therapy 9.7% in intervention group vs 5.5% in standard care group (p = not significant).
Painter, 2015^17^; Pyne, 2011^18^ | RCT; N = 249 | Three VA HIV clinics | Offsite HIV depression care team | HIV clinics | 3 | Response rate for depression at 6 months in intervention vs control was 33.3% vs 17.5% (p = 0.004); no difference at 12 months. Intervention patients also had greater improvements in HIV symptom severity but no differences in health-related QoL, medication prescribing or adherence. Modeling estimated with 96% probability that the incremental cost-effectiveness ratio was less than $20,000/quality-adjusted life year.
Described as Collaborative Care
Carney, 2016^12^ | RCT; N = 201 | One academic medical center (Wash U) | Collaborative depression care | Cardiology clinic | 3 | No statistically significant differences between groups in depression scales, QoL, hospitalization, mortality, satisfaction.
Bekelman, 2018^9^ | RCT; N = 314 | Three health systems: VA, urban safety net, academic health center | Psychosocial collaborative care | Usual care, which could be primary care + cardiology (77% of patients had cardiology) | 5 | No statistically significant difference between groups in disease-specific QoL. Depression symptoms, fatigue, and anxiety improved somewhat more in the intervention group.
Flicek, 2022^13^ | Case series with pre/post measures; N = 19 | One academic medical center (UNC) | Offsite collaborative care for behavioral health problems (anxiety and depression) | Academic center adult inflammatory bowel disease clinic | 3 | No statistically significant differences between pre- and post-measurement of anxiety and depression outcomes. Gastroenterology providers all highly agreed that the collaborative care program was a beneficial resource.
Huffman, 2014^14^ | RCT; N = 183 | One academic health center | Collaborative depression and anxiety care | Inpatient team + possibly primary care | 3 | Statistically significant improvement in the collaborative care patients compared to usual care in mental health quality of life, depressive symptoms, overall health-related quality of life, and general functioning. No difference in readmissions.
Variously described as Collaborative Care, then integrated care
Strong, 2008^23^ | RCT; N = 200 | One regional Scotland cancer center | Onsite or offsite one-on-one depression care delivered by trained nurses | Primary care and oncologist clinic care | 3 | Depression symptoms on the SCL-20 at 3, 6, and 12 months improved more in the intervention patients than usual care patients; modeling estimated that the intervention cost about $16,000/quality-adjusted life year.
Sharpe, 2014^22^ | RCT; N = 500 | Three Scotland cancer centers | Integrated collaborative depression care | Primary care and oncologist clinic care | 2 | Depression treatment response (50% reduction in SCL-20) was achieved by 62% of intervention patients and 17% of usual care patients, and intervention patients also had better outcomes on depression remission, anxiety, pain, fatigue, and several quality of life scale scores.
Walker, 2014^19^ | RCT; N = 142 | Three Scotland cancer centers | Onsite or offsite one-on-one depression care delivered by nurses | Primary care and oncologist clinic care | 2 | Depression symptoms on the SCL-20 at 12 to 32 weeks improved more in intervention patients than usual care patients, as did measures of anxiety, perceived quality of care, and several scale scores on cancer QoL.
Walker, 2022^20^ (based on Sharpe, 2014) | Mixed methods, post-only results; N = 51 health professionals; N = 32 patients | Oxford Cancer Center, part of the Oxford England hospitals | Offsite and onsite collaborative care for depression | Hospital-based cancer clinics, primary care | 3 | Patients and clinicians felt that screening for depression helped, that it was good to see a depression expert and good to have the program as part of cancer care, and that it relieved oncology clinicians of responsibility for managing depression.
Comanagement Program
Davis, 2023^21^ | Case series with pre/post measures; N = 22 | Academic, urban safety net hospital | Addiction-care team | Cardiology and (possibly) primary care | 2 | At the end of the 12-week program all patients were on guideline-recommended care, 3 had stopped using stimulants, acute care decreased 53% compared to pre-intervention use, and clinic no-show rate decreased.
Miscellaneous
Irwin, 2019^11^ | Case series with pre/post measures; N = 25 | One academic medical center (MGH) | Collaborative care for SMI mental health | Oncology clinic | 4 | Improvements in 2 clinician assessments, the Brief Psychiatric Rating Scale and the Clinical Global Impression-Severity; no difference in 2 patient-reported measures, the patient health questionnaire and the Functional Assessment of Cancer Therapy-General.

Notes.

a Levels of the CIHS Standard Framework for Levels of Integrated Healthcare (https://gcc02.safelinks.protection.outlook.com/?url=https%3A%2F%2Fwww.thenationalcouncil.org%2Fwp-content%2Fuploads%2F2020%2F01%2FCIHS_Framework_Final_charts.pdf%3Fdaf%3D375ateTbd56&data=05%7C02%7C%7C8ed2191b4bae45f04b0908dca1bebd55%7Ce95f1b23abaf45ee821db7ab251ab3bf%7C0%7C0%7C638563087813850593%7CUnknown%7CTWFpbGZsb3d8eyJWIjoiMC4wLjAwMDAiLCJQIjoiV2luMzIiLCJBTiI6Ik1haWwiLCJXVCI6Mn0%3D%7C0%7C%7C%7C&sdata=wQBS94HasBuR16Om4FF%2Be6XYrB2SYWAEVsi7qKvN1p0%3D&reserved=0).^5^ Level 1: Minimal Collaboration; Level 2: Basic Collaboration at a Distance; Level 3: Basic Collaboration Onsite; Level 4: Close Collaboration Onsite with Some System Integration; Level 5: Close Collaboration Approaching an Integrated Practice; Level 6: Full Collaboration in a Transformed/Merged Integrated Practice.

Abbreviations. QoL=quality of life.